# Appendix VII. Visit Preparation Instructions

Drink water—it is important that you stay hydrated during the health visit

Wear short sleeves.

Please have photo identification ready to show the health representative. Examples include a driver’s license, non‐driver’s ID, military ID, state ID, or passport.

Some of the tests are more accurate if you do not eat for 8 hours before the appointment. But you can still take part in the study no matter when you last ate. Would you like to know more about this topic?

If the participant says yes: If you choose not to eat for 8 hours before your appointment, you should still drink water and take your prescription medications as instructed by your doctor during that time. But avoid gum, breath mints, vitamins, and non‐prescription medicine. Also, if you need to take any of your prescription medications with food, please do so. Remember, if you do eat in the 8 hours before your appointment, you can still take part in the study, and most of your results will be unaffected.

During the home visit, our health representative will need to be close to you in order to take measurements such as height and blood pressure. Therefore, they are required towear full personal protective equipment including face shields. We recommend you wear a facemask at all times during the visit.

Read if necessary (Answers to possible participant questions)

Which tests are more accurate if I don’t eat for 8 hours before the appointment?

The tests for pre‐diabetes, diabetes, and cholesterol.

What if I have diabetes and take pills or insulin to treat it?

We will be testing to see how well your medicines are working to treat your diabetes. If your diabetes treatment plan will allow you to wait to take them until after your blood sample is taken, you can do so. Please consult with your medical provider if you have any questions about this. If you need to eat or drink with any of your medications, please do so. You can still take part in the study even if you do take your diabetes pills or insulin first.

What is personal protective equipment?

Personal protective equipment includes face shield, surgical mask, lab coat or long sleeves under scrubs, gloves, and close‐toed shoes.

Will you provide a mask?

We will offer you a mask to wear during the visit.