# Appendix VI. COVID-19 Screening Questions

Have you experienced any of the following symptoms in the past 48 hours:

fever or chills

cough

shortness of breath or difficulty breathing

fatigue

muscle or body aches

headache

new loss of taste or smell

sore throat

congestion or runny nose

nausea or vomiting

diarrhea

Within the past 14 days, have you been in close physical contact with a person who tested positive for COVID‐19 or has any symptoms of COVID‐19?

Read if necessary: Close physical contact means being 6 feet or closer for at least 15 minutes

Are you isolating or quarantining because you were diagnosed with COVID‐19, you may have been exposed to a person with COVID‐19, or are worried that you may be sick with COVID‐19?

Are you currently waiting on the results of a COVID‐19 test?