# Appendix V. Scheduling Scripts

[underlined: Voicemail script for scheduler and recruitment specialist:]

Hello, my name is . I’m calling on behalf of the CDC’s National Center forHealth Statistics. I’m trying to reach {participant name} about scheduling a home health visit.Please call our toll‐free number (1‐833‐996‐2771) and let us know what time would be convenient for you. That’s (1‐833‐996‐2771). Thank you. We look forward to hearing from you! ___

[underlined: Phone script for scheduler and recruitment specialist:]

Hello, my name is, may I please speak with (PARTICIPANT NAME)?

Participant not home or unavailable:

Can you please ask {him/her} to call me at 1‐833‐996‐2771? When is the best time to reach {participant name}?

Participant is available but person on the phone wants to know who is calling before handing the phone over:

I’m calling on behalf of the CDC’s National Center for Health Statistics.

Participant is on the line now but wasn’t the person who answered the phone:

Hello, my name is. [Continue with Speaking to the participant.]

Speaking to the participant:

I’m calling from the National Health Interview Survey Follow‐up Health Study to schedule your home health visit.

Read if necessary: You spoke with an interviewer recently about general health topics like doctor’s visits and health conditions and agreed to be contacted for this study.

[Answer any questions the respondent has.]

Before making the appointment, I need to ask about COVID‐19 symptoms you may have or possible exposure to someone with COVID‐19.

[Read COVID screening questions. (Appendix F)]

[If participant responds “YES” to any COVID screening question, schedule the participant’s home health visit for a date more than 14 days after the current date, if the study will still be active at that time.]

[If participant responds “No” to all COVID screening questions, schedule the appointment as soon as is convenient for the participant and possible given health representative schedules.]

There are a few ways you can prepare for the visit.

[Read visit preparation instructions. (Appendix G)]

Your home health visit is scheduled with (NAME OF HEALTH REPRESENTATIVE). How would you prefer {she/he} contact you to remind you of the appointment– phone, text, or email? There may be fees to get a text message, depending on your plan.

Read if necessary: NCHS will not reimburse you for any text message charges.

[Enter preferred contact mode and phone number or email address in the scheduling system.]

[Provide the toll free number to the participant to call if they need to cancel or reschedule the appointment (1‐833‐996‐2771).]

Thank you for agreeing to take part in this study.

[underlined: Computer generated email and text message template]

Email subject line/first line of the text message: Please call to schedule your CDC/NCHS home health visit

Thank you for agreeing to take part in our study.

Please call our toll‐free number (1‐833‐996‐2771) to schedule your home health visit at a time that is convenient for you.

We look forward to hearing from you!

National Center for Health Statistics Centers for Disease Control and Prevention