# Appendix IV. Follow-up Brochure

Image of follow-up brochure to the National Health Interview Survey Follow-up Health Study. First side shows four panels. Second side shows different faces with comments about participating.