# Appendix III. Study Brochure

Image of brochure for the National Health Interview Survey Follow-up Health Study. First side is two panels. Second side shows two graphics of people with questions and answers about the survey.