# Appendix II. National Health Interview Survey Follow-up Health Study-related Questions for Field Representative

## Computer-assisted Personal Interviewing Instrument Completed by Field Representative

The following questions were included in the section of the National Health Interview Survey instrument with questions answered by the field representative. These questions were displayed only when the Sample Adult was selected for the Follow‐up Health Study and the interview was conducted in English not via a proxy.

## BIOBROCHURE

Did you give the Sample Adult a copy of the Follow‐up Health Study brochure?

1. Yes
2. No
3. I offered it but the Sample Adult refused to take it
4. Interview was over the phone

If the Sample Adult refused to participate and then refused to explain why (RF or DK in response to BIORFWHY_A) go to BIORFWHYFR

## BIORFWHYFR

What REASON(S), if any, did the Sample Adult give for REFUSING to be contacted to schedule the home health visit?

If the Sample Adult agreed to participate and gave a valid phone number, go to BIOOKWHYFR

## BIOOKWHYFR

What REASON(S), if any, did the Sample Adult give for AGREEING to be contacted to schedule the home health visit? Enter 'N' for none.