# Appendix XVII. Technical Notes

The measures presented in this report are described below, organized by research question.

## Research Question 1: Participation, Component Completion, Biological Measure Analysis, and Reason for Nonparticipation

### Participation and Component Completion Measures

Agreed—The Sample Adult (Sample Adult) gave permission for their name, phone number, and other contact information to be passed to the contractor.

Spoke with study staff—Sample Adult spoke with study staff on the phone.

Scheduled appointment—Sample Adult scheduled an appointment for a home visit.

Completed examination—Sample Adult scheduled an appointment and then provided consent when the health representative visited their home at the scheduled time. All Sample Adults who provided consent then completed at least one component of the protocol, and most completed all. All the Sample Adults who provided consent when the health representative visited their home were considered to have completed the examination, no matter how many components they completed.

Completed height, weight, and waist circumference—The health representative successfully measured the Sample Adult’s height, weight, and waist circumference.

Completed blood pressure—The health representative successfully measured the Sample Adult’s blood pressure and pulse.

Provided a urine sample—Sample Adult provided a urine sample of adequate volume to send to the laboratory for processing.

Provided a blood sample—The health representative was able to collect a blood sample of adequate volume to send to the laboratory for processing.

Completed checkout—Sample Adult received both the initial report of findings and the prepaid gift card, whether or not the participant completed the post-examination survey.

Completed all parts of the examination—Sample Adult completed the height, weight, waist circumference, blood pressure, and checkout components and also provided a blood and urine sample.

Fasted before the examination—Sample Adult fasted for at least 8 hours before the examination.

### Biospecimen Processing Measures

Received complete, partial, or no blood test results—Sample Adult provided a blood sample of adequate volume to send to the laboratory for processing and received complete, partial, or no blood test results.

Receive complete, partial, or no urine test results—Sample Adult provided a urine sample of adequate volume to send to the laboratory for processing and received complete, partial, or no urine test results.

### Nonparticipation Measures

Sample Adults whose contact information was passed to the contractor but who never completed an examination were categorized by the type of interaction they had with the study staff.

Never spoke to study staff—Sample Adult spoke with neither schedulers nor recruitment specialists.

Maximum contacts—Includes Sample Adults who spoke with a scheduler but never scheduled an appointment before the maximum number of contacts was reached, could not be reached after a scheduled appointment did not occur so the appointment was not rescheduled, or called and left a message or sent an e-mail but never spoke to a scheduler or recruitment specialist.

Refusal—Sample Adult refused the study after speaking with a scheduler or after scheduling an appointment. Note that while the scheduling and refusal conversion protocol took different paths depending on whether the scheduler or refusal converter determined a Sample Adult’s behavior to be a hard or soft refusal, there is only one outcome code that refers to verbally refusing to participate.

No show—Sample Adult scheduled one or more appointments but did not keep an initial or rescheduled appointment and did not reschedule (again).

Other—All other Sample Adults whose contact information was passed to the contractor but did not start an examination.

## Research Question 2: Reason for Refusal, Motivation for Participation, and Respondent Concern Measures

### Reasons for Refusal at Interview

If the Sample Adult refused to be contacted for the National Health Interview Survey Follow-up Health Study (NHIS FHS) when asked by the field representative (FR), the FR asked, “There are several reasons why someone may not want to take part in a study. Please tell me the main reason why you don’t want to take part in this study?” The Sample Adult’s verbatim responses to this question were coded into categories as described in “Invitation to Study and Collection of Permission to Be Contacted.”

### Motivation for Participation at NHIS Interview

If the Sample Adult agreed to be contacted for NHIS FHS and gave a valid phone number when asked by the FR, then the paradata section at the end of the NHIS instrument asked the FR “What reasons, if any, did the Sample Adult give for agreeing to be contacted to schedule a home health visit?” The FR’s verbatim responses to this question were coded into categories.

### Reasons for Refusal at Scheduling

If the Sample Adult refused, the scheduler recorded the reason for refusal, if the Sample Adult gave one.

### Participant Concerns Assessed in Post-examination Survey

During the post-examination survey, participants were asked if they had any concerns about participating in the study and to describe their concerns. Westat staff coded the verbatim answers provided into nine categories.

### Participant Motivation Assessed in Post-examination Survey

To assess factors that motivated participants to complete the home examination, they were asked after the examination whether any of four reasons contributed to their decision to participate. They were also allowed to provide a reason other than the precoded reasons. After reporting all reasons that impacted their decision, participants were asked to identify the main reason. The answer options provided were the following:

- Free test results
- $75 prepaid gift card
- Help with health efforts in the United States
- Improve information used by policymakers
- Some other reason

## Research Question 3: Operational Challenges of Gaining Sample Adult Initial Agreement to Participate

### Mean Time FRs Spent Reading Text Describing NHIS FHS to Sample Adult

The text describing NHIS FHS is shown under the headings BIOINT1_A, BIOINT2_A, and BIONAME_A in Appendix I. The amount of time each FR spent reading this text to each Sample Adult was calculated by subtracting the time stamp recorded by the NHIS instrument when the FR entered the BIOINT1_A screen and the time stamp recorded by the NHIS instrument when the FR exited the BIONAME_A screen.

### Expected Time FRs Spent Reading Text Describing NHIS FHS to Sample Adult

Six National Center for Health Statistics members of the NHIS FHS planning team timed themselves reading the text, as described in the previous measure, at a leisurely pace, three times. The mean of those 18 times was the expected duration.

### FR Survey Measures

The results from the web survey administered to the NHIS FRs who had completed at least one NHIS FHS interview were calculated by the Center for Behavioral Science Methods, the same organization at the U.S. Census Bureau that collected the data and conducted the post-FHS FR focus groups. The measures from that analysis included in this report are listed.

Feeling of preparation to ask Sample Adults about NHIS FHS—FRs were asked, “After you received your Commerce Learning Center training, how prepared were you to ask Sample Adults about the NHIS Biomeasure Follow-up Health Study?” FRs could answer “very prepared,” “somewhat prepared,” “neither prepared nor unprepared,” “somewhat unprepared,” or “very unprepared.”

Need to rephrase the questions about being contacted for the study—FRs were asked, “In general, how often did you need to rephrase questions in the BIO section in your own words to make this section easier to administer?” FRs could answer “always,” “most of the time,” “sometimes,” or “never.”

Could read the introduction screens without being interrupted by Sample Adult—FRs were asked, “How often were you able to get through the introduction screens in the BIO sections without being interrupted by the Sample Adult?” FRs could answer “always,” “most of the time,” “sometimes,” or “never.”

Use of study tools in convincing reluctant Sample Adults to participate—FRs were asked, “How helpful were the following tools for convincing reluctant Sample Adults to participate in the NHIS Biomeasure Follow-up Health Study, CLC BIO section training, FAQs in the instrument, $75 incentive, memo with suggested language.” FRs could answer “very helpful,” “somewhat helpful,” “neither helpful nor unhelpful,” “somewhat unhelpful,” “very unhelpful,” “I don’t remember using this tool,” or “I didn’t use this tool.”

Whether it would be easier to convince Sample Adults to provide their contact information for FHS if they could have told them in advance about the study—FRs were asked, “Would it be easier for you to convince Sample Adults to provide their contact information for the NHIS Biomeasure Follow-up Health Study if you could tell them in advance about the study?” FRs could answer “yes,” “no,” or “I’m not sure.”

Whether it would be easier to convince Sample Adults to provide their contact information for FHS if the materials provided more detail on how the data would be used or how participation would benefit the Sample Adult—FRs were asked, “Please select what changes to the materials you think would be helpful for convincing reluctant Sample Adults to participate in the NHIS Biomeasure Follow-up Health Study.” FRs could select answer options including providing more detailed information about how the data will be used, and providing more information about how participation will benefit the Sample Adult.

Helpfulness of incentive for convincing reluctant Sample Adults to participate—FRs were asked, “Sample Adults are now offered a $75 incentive for participating in the NHIS Biomeasures Follow-up Health Study. How can this incentive be improved for the future?” FRs could type a verbatim response. These responses were coded by Center for Behavioral Science Methods staff into the following categories:

- Increase incentive or add more benefits
- Talk about incentive before invitation
- Fine as is
- Incentive did not impact decision to participate

Ease or difficulty of convincing Sample Adults to participate—FRs were asked, “How easy or difficult was it to convince Sample Adults to participate in the Biomeasure Follow-up Health Study?” FRs could answer “very easy,” “somewhat easy,” “neither easy nor difficult,” “somewhat difficult,” or “very difficult.”

Concern that administering NHIS FHS would discourage Sample Adult from completing Sample Child interview—FRs were asked, “How concerned were you that administering the BIO section would affect the Sample Adult’s willingness to complete the Sample Child interview?” FRs could answer “very concerned,” “somewhat concerned,” “neither concerned nor unconcerned,” “unconcerned,” or “very unconcerned.”

### NHIS Interview Mode

At the end of the NHIS interview, the FR enters whether the Sample Adult interview was conducted in person, by phone, or partially in person and partially by phone. Interview mode was coded as in person if the first option was selected, and by phone if either of the second two options was selected.

## Research Question 4: Operational Challenges of Scheduling Home Health Visit Appointment

### Reasons Appointment Was Eligible for Reschedule

Appointments eligible for reschedule were categorized into three groups—eligible for a reschedule due to a participant reason, eligible for reschedule due to a health representative reason, and eligible for a reschedule due to both a participant and a health representative reason.

### Post-examination Survey Measures: Ease of Appointment Scheduling

Participants were asked, “How easy or difficult was scheduling your appointment?” They could respond “very easy,” “easy,” “difficult,” or “very difficult.” Respondents who answered that scheduling the appointment was anything other than very easy were then asked, “In what ways could the appointment scheduling be improved?”

## Research Question 5: Operational Challenges of Conducting In-home Health Visit

### Examination Durations

Total examination duration was calculated as the time between completion of the home visit consent process and the completion of the checkout component.

The duration of the examination components was calculated as the time between that component’s start and end time stamp. Of the 176 completed cases, 7 cases with durations shorter than 20 minutes and 6 cases with durations longer than 70 minutes were excluded. According to the contractor, very short durations were likely cases in which the health representative completed data entry at the end of the visit. The very long durations included cases where the laptop was left open after the visit was complete and two cases that spanned two home visits.

### Post-examination Survey Measures: Burden of Participation

Participants were asked, “How easy or difficult was it for you to take part in this home visit?” Response options were “very easy,” “easy,” “difficult,” or “very difficult.”

Participants were asked, “How easy or difficult was it to get your questions answered?” Response options were “very easy,” “easy,” “difficult,” or “very difficult.”

Participants were asked, “How likely or unlikely are you to participate in a study like this in the future?” Response options were “very likely,” “likely,” “unlikely,” or “very unlikely.”

### Number of Days Between NHIS Interview and Home Visit

Number of days was coded into the following categories: 1–14 days, 15–28 days, 29–49 days, and 50 days or more.

## Research Question 6: Operational Challenges of Packaging, Shipping, and Analyzing Biospecimens and Reporting Results of Home Health Examinations

Five reasons were documented for incomplete urine and blood tests:

- Incomplete or inaccurate laboratory requisition forms
- Packaging problems
- Centrifuging problems
- Laboratory error
- Inadequate urine quantity

## Vital and Health Statistics Series Descriptions

### Active Series

Series 1. Programs and Collection Procedures

Reports describe the programs and data systems of the National Center for Health Statistics, and the data collection and survey methods used. Series 1 reports also include definitions, survey design, estimation, and other material necessary for understanding and analyzing the data.

Series 2. Data Evaluation and Methods Research

Reports present new statistical methodology including experimental tests of new survey methods, studies of vital and health statistics collection methods, new analytical techniques, objective evaluations of reliability of collected data, and contributions to statistical theory. Reports also include comparison of U.S. methodology with those of other countries.

Series 3. Analytical and Epidemiological Studies

Reports present data analyses, epidemiological studies, and descriptive statistics based on national surveys and data systems. As of 2015, Series 3 includes reports that would have previously been published in Series 5, 10–15, and 20–23.

Discontinued Series

Series 4. Documents and Committee Reports

Reports contain findings of major committees concerned with vital and health statistics and documents. The last Series 4 report was published in 2002; these are now included in Series 2 or another appropriate series.

Series 5. International Vital and Health Statistics Reports

Reports present analytical and descriptive comparisons of U.S. vital and health statistics with those of other countries. The last Series 5 report was published in 2003; these are now included in Series 3 or another appropriate series.

Series 6. Cognition and Survey Measurement

Reports use methods of cognitive science to design, evaluate, and test survey instruments. The last Series 6 report was published in 1999; these are now included in Series 2.

Series 10. Data From the National Health Interview Survey

Reports present statistics on illness; accidental injuries; disability; use of hospital, medical, dental, and other services; and other health-related topics. As of 2015, these are included in Series 3.

Series 11. Data From the National Health Examination Survey, the National Health and Nutrition Examination Surveys, and the Hispanic Health and Nutrition Examination Survey

Reports present 1) estimates of the medically defined prevalence of specific diseases in the United States and the distribution of the population with respect to physical, physiological, and psychological characteristics and 2) analysis of relationships among the various measurements. As of 2015, these are included in Series 3.

Series 12. Data From the Institutionalized Population Surveys

The last Series 12 report was published in 1974; these reports were included in Series 13, and as of 2015 are in Series 3.

Series 13. Data From the National Health Care Survey

Reports present statistics on health resources and use of health care resources based on data collected from health care providers and provider records. As of 2015, these reports are included in Series 3.[[pg;]]

Series 14. Data on Health Resources: Manpower and Facilities

The last Series 14 report was published in 1989; these reports were included in Series 13, and are now included in Series 3.

Series 15. Data From Special Surveys

Reports contain statistics on health and health-related topics from surveys that are not a part of the continuing data systems of the National Center for Health Statistics. The last Series 15 report was published in 2002; these reports are now included in Series 3.

Series 16. Compilations of Advance Data From Vital and Health Statistics

The last Series 16 report was published in 1996. All reports are available online; compilations are no longer needed.

Series 20. Data on Mortality

Reports include analyses by cause of death and demographic variables, and geographic and trend analyses. The last Series 20 report was published in 2007; these reports are now included in Series 3.

Series 21. Data on Natality, Marriage, and Divorce

Reports include analyses by health and demographic variables, and geographic and trend analyses. The last Series 21 report was published in 2006; these reports are now included in Series 3.

Series 22. Data From the National Mortality and Natality Surveys

The last Series 22 report was published in 1973. Reports from sample surveys of vital records were included in Series 20 or 21, and are now included in Series 3.

Series 23. Data From the National Survey of Family Growth

Reports contain statistics on factors that affect birth rates, factors affecting the formation and dissolution of families, and behavior related to the risk of HIV and other sexually transmitted diseases. The last Series 23 report was published in 2011; these reports are now included in Series 3.

Series 24. Compilations of Data on Natality, Mortality, Marriage, and Divorce

The last Series 24 report was published in 1996. All reports are available online; compilations are no longer needed.