# Appendix XVI. Final Report of Findings

Image of letter sent to participants describing the results of the health measures taken as part of the National Health Interview Survey Follow-up Health Study.