# Appendix XV. Preliminary Report of Findings

NHIS Follow-up Health Study REPORT OF FINDINGS

Date of Home Visit:____________________________

Participant Name:____________________________

Participant ID:____________________________

This report provides you with results from today’s body and blood pressure measurements. You will receive your results from the laboratory blood and urine tests in the mail in several weeks.

The NHIS Follow-up Health Study visit is not intended to be a substitute for visits to your medical care provider. Your health care provider can help you understand your study results in the enclosed report.

Please keep this document in a safe place so that you can control who sees it. NCHS can only protect information that is inside NCHS systems.

If you have any questions about your results, you can call our Medical Officer, Dr. Tony Nguyen, toll-free at 1-833-872-0534 between 9:00 AM and 4:00 PM Eastern Time, Monday through Friday.

Body Measurements

Height: ____ ft ____ inches

□This measurement was not done for you during the home visit.

Weight: _______ lbs.

□This measurement was not done for you during the home visit.

Waist Circumference: _______ inches

□This measurement was not done for you during the home visit.

Body Mass Index (BMI): _____

The Body Mass Index (BMI) is used to define the categories of underweight, healthy weight, overweight, and obesity. BMI is calculated from measured height and weight using the formula below:

BMI=weight (lbs.) ÷ height (in.) ÷ height (in.) x 703.

1) Your blood pressure today is within the normal range.*

2) Your blood pressure today is elevated. Based on national guidelines for the treatment of hypertension*, you should take this report to a health care provider within the next 3-6 months to have your blood pressure rechecked.

3) Your blood pressure today is high. Based on national guidelines for the treatment of hypertension*, you should take this report to a health care provider within two weeks.

4) Your blood pressure today is very high. Based on the national guidelines for the treatment of hypertension*, you should take this report to a health care provider within two weeks.

5) Your blood pressure today is severely high. Based on national guidelines for the treatment of hypertension*, this level warrants immediate attention by a health care provider. Our Medical Officer will contact you to answer any questions you may have.

*ACC/AHA Hypertension Guidelines for the Prevention, Detection, Evaluation, and Management of High Blood Pressure in Adults, American Journal of Hypertension, 31(2), 2018, p133-35. These measurements were obtained as part of a health study and do not represent a medical diagnosis. Interpretation of these measurements must be made by your physician.