# Appendix XIV. Post-examination Survey

We would like to ask you a few questions about your study experience. Your feedback will help us improve studies like this in the future. Please answer honestly. There are no right or wrong answers.

How easy or difficult was scheduling your appointment? Very easy, easy, difficult, or very difficult? (Don’t read: Don’t know, refused)

(Ask if response to Q1 is easy, difficult, or very difficult): In what ways could the appointment scheduling be improved?

How easy or difficult was it to get your questions answered? Very easy, easy, difficult, or very difficult? I didn’t have any questions (Not read to respondent, code only if volunteered). (Don’t read: Don’t know, refused) (Ask if response to Q3 is easy, difficult, or very difficult): In what ways could we better answer your questions?

How easy or difficult was it for you to take part in this home visit? Very easy, easy, difficult, or very difficult? (Don’t read: Don’t know, refused)

(Ask if response to Q5 is easy, difficult, or very difficult): In what ways could the home visit be made easier and more convenient?

How likely or unlikely are you to participate in a study like this in the future? Very likely, likely, unlikely, or very unlikely? (Don’t read: Don’t know, refused)

What were your concerns, if any, about participating?

Please tell me yes or no, whether you took part in this study for any of the following reasons:

(Read a through f) (Answer options on the screen: Yes, No Don’t read: Don’t know, refused)

Free test results

The $75 prepaid card

Help with health efforts in the United States

Improve information used by policymakers

Some other reason

(Ask if response to 9f was yes) What was that reason?______________________________________________

(Ask if more than 1 response selected in Q9 a‐f) What was your main reason for taking part in this follow‐up study? Pick one or specify

Free test results

The $75 prepaid card

Help with health efforts in the United States

Improve information used by policymakers

Other ___________________________________________________________