# Appendix XIII. Measurement and Laboratory Test Explanation

NHIS Follow-Up Health Study

Health Measurements and Laboratory Tests on Blood & Urine
Below are brief descriptions of the health measurements, urine tests, and blood tests included in this health study. Please note that this study does not test blood and urine for drugs, alcohol, pregnancy or genetic ancestry.
[underlined: Health Measurements] | [underlined: Blood Tests]
Your height and weight will be measured to calculate your Body Mass Index (BMI). | Diabetes Screen
Your waist circumference will be measured. Your blood pressure and pulse will be taken. | Hemoglobin A1c: Gives information about your average blood sugar level during the past 2–3 months. High levels are seen in diabetes.
[underlined: Urine Tests] | Glucose: The amount of sugar in your blood. Glucose is an important source of energy for all body organs and functions. High levels are seen in diabetes.
Creatinine: A waste product of normal muscle breakdown filtered by the kidneys out of your blood into your urine. This test shows how well your kidneys are working. | Liver and Kidney Function Tests
Glucose: A type of sugar. It is your body's main source of energy. If too much glucose gets into the blood, the extra glucose will be eliminated through your urine. Hemoglobin: The molecule in red blood cells. This test looks for the presence of blood in your urine. Microalbumin: A test to detect very small levels of albumin in urine. The test is used to detect early signs of kidney damage in people who are at risk of developing kidney disease. Protein: A test to detect albumin in urine. The test is used to detect kidney damage. Protein:Creatinine Ratio (Calculated): A test to screen for excess protein in the urine. It can help your doctor evaluate and monitor kidney function, and detect kidney damage. | Albumin: A protein in your blood. Albumin keeps fluid from leaking out of blood vessels, nourishes tissues, and transports hormones, vitamins, drugs, and substances like calcium throughout the body. Albumin: Globulin Ratio: This test is used to screen for and help diagnose certain diseases or disorders. Alanine Aminotransferase (ALT): ALT is an enzyme involved in breakdown of body chemicals and is mostly found in the liver. ALT levels reflect the health of your liver. Alkaline Phosphatase: A blood enzyme that comes from liver and bone cells. Aspartate Aminotransferase (AST): AST is an enzyme involved in the breakdown of body chemicals, and AST levels reflect the health of your liver. Bicarbonate: A molecule in blood that shows the balance between your breathing and chemical systems. Bilirubin: A chemical produced when hemoglobin breaks down. Bilirubin is broken down by the liver and then it becomes a waste product. It is used as a measure of the health of your liver. Blood Urea Nitrogen (BUN): Urea is a waste product that your kidneys filter out of your blood. This test helps show how well your kidneys are working. Calcium: A mineral found mostly in the bones. It is needed for muscle and nerve action, bone strength, and blood clotting. Chloride: One of the electrolytes found in your body. Chloride plays an important role in the balance of body fluids. Creatinine: A waste product of normal muscle breakdown filtered by the kidneys out of your blood into your urine. This test shows how well your kidneys are working. Globulin: A protein in the blood. Globulins play an important role in liver function, blood clotting, and fighting infection. Glomerular Filtration Rate (estimated): This test is used to detect chronic kidney disease (CKD), as well as monitor CKD progression and response to therapy. Potassium: A nutrient found in your body’s cells. Potassium helps control muscle and nerve actions. Protein: The total amount of protein (both albumin and globulin) in the fluid part of your blood. Protein is an important part of all your body’s cells and tissues. Sodium: One of the electrolytes found in body fluids. Sodium plays an important role in the balance of body fluids and in muscle and nerve actions.
| Cholesterol Tests
| Total Cholesterol: A fat substance normally found in the bloodstream and in all your body's cells. Too much cholesterol is a major risk for a heart attack and stroke. Total Cholesterol:HDL Ratio: Compares the total cholesterol to the HDL, or good, cholesterol. This test can help your doctor determine your risk of heart problems or stroke. High Density Lipoprotein (HDL) Cholesterol: HDL cholesterol is known as the “good” cholesterol because it helps remove cholesterol from the body cells and helps prevent fatty buildup in blood vessels. Low Density Lipoprotein (LDL) Cholesterol: LDL cholesterol is known as the “bad” cholesterol because it can lead to cholesterol buildup in your body cells and can lead to fatty buildup in blood vessels. Non-HDL Cholesterol: A test to measure how much of the “bad” cholesterol you have in your blood. It can help your doctor evaluate your risk for heart disease. Triglycerides: A fat in the blood. High levels can lead to heart disease and stroke.
| Anemia Screen
| Hemoglobin: The molecule in red blood cells that carries oxygen to all body tissues.