# Appendix XII. Informed Consent Form

Description of the various health measures included in the National Health Interview Survey Follow-up Health Study.