# Appendix X. Home Visit Kit Inventory

The Table shows the items included in the National Health Interview Survey Follow-up Health Study home visit kit carried by the health representative.

Table

National Health Interview Survey Follow-up Health Study home visit kit inventory

Item | Quantity
General supplies:
Disposable 6x6 pad | 1
Disposable patient towel | 1
Trash bag | 1
Sanitizing wipes | 2
IATA^1^ shipping container | 1
Refrigerant pack | 1
Cellulose wadding | 1
FedEx Air bill (on IATA shipping container) | 1
Surgical mask | 1
Disposable stylus | 1
Tape strips | 2
Biohazard bag | 1
Exempt human specimen label (on IATA shipping container) | 1
Blood collection supplies:
Alcohol prep pad | 2
Disposable tourniquet | 1
4 mL EDTA vacutainer | 1
10 mL SST^2^ vacutainer | 2
Bandage | 1
Gauze pad | 2
21 g needle | 1
23 g butterfly needle | 1
Vacutainer hub | 2
Nitrile gloves | 1
Sample ID label | 3
Specimen transport bag | 1
Urine collection supplies:
Collection container | 1
Transport tube | 2
Plastic transfer pipet | 1
Nitrile gloves | 1
Sample ID label | 3
Specimen transport bag | 2
Paper supplies:
Home visit kit inventory sheet | 1
Quest Diagnostics requisition form (1 blood, 1 urine) | 2
Consent form | 1
Test and measurement handout | 1
Report of findings | 1
Visa card FAQs | 1
Visa card and carrier sheet | 1

1 International Air Transport Association.

2 Serum separator tube.

SOURCE: National Center for Health Statistics, National Health Interview Survey Follow-up Health Study, 2021.