# Appendix I. Follow-up Health Study Introduction Questions in National Health Interview Survey Instrument

## Survey Instrument

### BIOINT1_A

Before we finish today, the study sponsor, the National Center for Health Statistics, or NCHS, which is part of the CDC, would like to invite you to participate in a follow‐up health study. The goal of the study is to develop methods to collect important health data that cannot be obtained from an interview. If you participate you will receive $75. The Census Bureau does not have a role in this study. For this study, a trained health representative will come to your home at a day and time that is convenient for you. The health representative will measure your height, weight, waist, blood pressure, resting heart rate and will collect a blood sample. You will also be asked to provide a urine sample and feedback about your study experience. Your blood and urine will be tested for standard health measures such as liver and kidney function. You will receive your personal results and, as mentioned, $75. At the end of the study, NCHS will combine your results with the results of all other participants. This information will ONLY be used for statistical purposes.

Read if necessary: Strict federal laws prevent NCHS and its contractors from releasing information that could identify you or your family to anyone else without your permission. All identifying information is removed from the data.

If the respondent refuses, go to BIORFWHY_A

### BIOINT2_A

This visit will take about an hour and your participation is voluntary. If you choose, you can complete just part of the study.

If the interview is in person: Here is a brochure that explains in more detail what the study will be about. *Hand over brochure.

If the interview is over the phone: I am happy to answer questions and I can also send you a brochure explaining more about the study. *If the respondent agrees to be contacted, mail study brochure after the end of the interview.

If the respondent refuses, go to BIORFWHY_A

### BIONAME_A

ExamOne, a Quest Diagnostics company, is collecting the study data for NCHS. May NCHS provide them with your name, age, and gender, along with your address, and phone number so they may contact you to schedule an appointment?

Read if necessary: ExamOne will ONLY use this information for the purpose of scheduling and completing your home health visit. No other information about your health will be provided to ExamOne. Read if necessary: Study staff will use your age and gender to interpret the results from your home health visit.

If the respondent says anything other than yes (no, refuse, don’t know), go to BIORFWHY_A

### BIOPHONE_A

Your phone number is needed to participate in the follow‐up study. Could you please provide a number?

If the respondent does not provide a phone number, go to BIORFWHY_A

### BIODAY_A

What are the best days for the study representative to contact you? Would you say weekdays, weekends, or both?

### BIOTIME_A

What is the best time of day for the study representative to contact you?

Would you say mornings, afternoons, evenings, or anytime? Enter all that apply

BIOTEXT_A: If they have difficulty reaching you by phone, is it OK for a study representative to text you?

If respondent says phone can't receive texts ("it's a landline"), enter 'no'.

### BIOEMAIL_A

If they have difficulty reaching you, the study representative could try contacting you via e‐mail. May I have your e‐mail address?

Enter e‐mail address. If respondent does not want to provide an e‐mail address enter 'Refused'. If respondent does not have an e‐mail address enter 'N'.

### BIORFWHY_A

There are several reasons why someone may not want to take part in a study.

Please tell me the main reason why you don't want to take part in this study?

Read if necessary: The study sponsor wants to understand your concerns so they can plan better versions of this study in the future.

Use your best judgement. If respondent is hostile or agitated, don't ask this question, just enter CTRL‐R. There will be an opportunity in the Back section for you to record your impression of the respondent's reason(s) for refusal.