# Discussion

This report evaluates the performance of an eMKF approach for estimating health outcomes for small subpopulations where statistical reliability may be of concern. To evaluate the performance of the eMKF approach under various scenarios commonly encountered by NCHS analysts, several simulated data sets were constructed reflecting a range of sample sizes, high or low prevalence outcomes, and linear and nonlinear trend forms with unequally spaced time intervals, along with shared or unique temporal trends by population subgroup. Like evaluations of the original MKF macro and procedures (9,10), findings suggest that using the eMKF approach offers substantial gains in estimate accuracy and precision (that is, lower RMSE) in nearly all cases examined in these simulations, with larger gains for smaller subgroups.

When evaluating the RMSE relative to the true direct NHIS estimates from the total sample, RMSEs were smaller for the model-based estimates compared with the direct subsample estimates. This suggests that the eMKF estimates offer advantages in terms of overall accuracy and precision relative to the direct estimates from smaller samples when compared with the true population values. This should reassure analysts who are considering using the eMKF macro to generate model-based estimates with NCHS data systems. More accurate and precise estimates can be obtained regardless of sample size. However, direct estimates may still likely be preferred when available as they can usually be assumed to be unbiased (16), and this consideration may be of greater importance to analysts and data users than improvements in precision or RMSE. In other cases, between-group comparisons may be of interest, where having more precise estimates would be useful in assessing whether significant differences exist between groups. Results shown in this report suggest that the potential increase in bias associated with using the eMKF approach is likely small on average but varies by subgroup. Model-based estimates were generally within one SE or less of the direct estimates, on average, although larger standardized differences were seen for selected individual subgroups, ranging up to 4.6 in one case where the estimates were based on a sample size of 12 respondents. Percentage increases in equivalent sample size were also variable by subgroup but tended to be larger in magnitude for smaller sample sizes. This is likely an important benefit in using the eMKF approach to generate estimates for smaller racial or ethnic subgroups typically aggregated into a larger other or multiple-race non-Hispanic category or an overall Hispanic or Latino category.

While improvements in precision may not be necessary for large subgroups where direct survey estimates are already sufficiently reliable, results of this evaluation indicate that even in those cases, the costs of using the eMKF approach (as in potentially increased bias and computation time) are relatively small compared with the benefits. In previous evaluations of the original MKF macro and procedures, reductions in RMSE could be equivalent to a sixfold increase in sample size, on average, across the different racial and ethnic groups considered (10). In this report, average increases in equivalent sample sizes ranged from 0% to 420% across the various simulation scenarios. Given the cost of oversampling select subgroups to attain statistically reliable estimates for certain subdomains, the eMKF macro offers an exceptionally low-cost alternative.

Comparing the earlier MKF macro with the model averaging option available in the current eMKF macro, results illustrate that in most cases examined, the BMA up to cubic trends with random variances provided the largest increase in equivalent sample sizes and the lowest RRMSE. While a few examples occurred where the linear model outperformed the BMA model, all the model-based approaches offered improvements in precision and increases in equivalent sample size. Results of this comparison suggest that the BMA option with up to cubic trends is likely a reasonable default choice in most cases. An alternative model (linear or quadratic) may be more advantageous in terms of RMSE in some instances, predicting which model will be optimal may be difficult. If it is clear beforehand that underlying trends are truly linear or quadratic, analysts may opt to specify the assumed trend form rather than starting with the BMA up to cubic trends option.

## Limitations and Considerations for Using the eMKF Macro

In some cases, RRMSEs could be greater than 1 for larger groups where more bias outweighs the increased precision of the model-based estimates. Generally, in cases where the RRMSE is greater than 1, the direct estimates would be preferred over the model-based estimates. Analysts should review the eMKF output closely to identify groups where the model-based estimates may be inferior to the direct estimates, although this would be expected to occur very infrequently. Note also that the output of the eMKF macro shows the RRMSE comparing the model-based estimates to the direct estimates used as input. Although the direct estimates are unbiased under repeated samples, only one sample is observed in practice, and estimates may differ from the true population values. In other words, the observed direct estimates based on a single sample may not represent a true gold standard to compare with model-based estimates, which is why comparisons using simulated data were used in this analysis.

Several different simulated scenarios were evaluated in this report to examine performance of the eMKF macro under conditions commonly encountered by analysts of NCHS data, but these simulated scenarios are not exhaustive. Further evaluation of the eMKF macro will be important to identify additional limitations or potential refinements in the future. While one of the objectives of this evaluation was to determine rules of thumb for when the eMKF macro may not be advantageous, no clear thresholds for sample size, prevalence, or underlying trend form clearly resulted in inferior eMKF estimates (relative to the direct estimates). Similarly, no clear rules of thumb were identified to determine which eMKF model would be optimal for a given analysis, though the BMA up to cubic trends option likely offers a reasonable default selection, given that this model captured all trend forms well from linear to cubic, based on simulated NHANES data.

Analysts should be aware that in cases where trends are unique by group (as in different slopes), and when more complicated underlying trends occur (cubic compared with linear or quadratic), smaller gains in precision and overall accuracy were associated with the model-based estimates than when trends were shared across groups (as in common slopes). In these cases where trends are more variable either over time or across subgroups, the advantages of “borrowing strength” are not as large as in simpler cases where common linear trends are shared across groups. Note that given that the eMKF approach borrows strength across subgroups, the magnitude of estimated disparities may be biased for smaller subpopulations subject to more smoothing. For example, estimates for a small subgroup with extremely poor health outcomes may be smoothed toward those of a larger reference group with better health outcomes. In those cases, analysts should be aware that disparities between these groups may be understated.

While the eMKF macro and models provide an approach for generating more precise model-based estimates for subgroups where direct estimates do not meet existing statistical reliability standards, these methods cannot be used when data are completely missing for some subgroups. As a result, if some population groups are not sampled in some time periods, analysts will need to combine or coarsen the data so that at least some sample appears in each time period. In these cases where some coarsening or aggregation may be necessary, consider if the composition of the groups may change over time, which could contribute to increased bias or variance of the estimates. For example, if American Indian or Alaska Native, Asian, and other or multiple race people are included in one larger group, estimates and related trends could be affected by sampling variability or changes in the proportion of that larger group represented by each racial and ethnic subgroup.

Based on the findings presented in this report showing large improvements in precision when using model-based estimates, analysts are advised to avoid filling in suppressed cells with model-based estimates while showing direct estimates for other groups where presentation standards are met. Given the impact of the model-based approach on precision demonstrated in this evaluation, comparing a model-based estimate for one population subgroup with a direct estimate for a larger population subgroup would be inappropriate. Instead, presenting a set of model-based estimates for all groups in addition to available direct estimates would be preferred. The main benefit of using the eMKF approach is anticipated to be in providing more reliable estimates for small subgroups when direct estimates would otherwise be suppressed, or when additional precision may improve statistical power for between-group comparisons when estimates for some subgroups are highly variable. However, the eMKF approach could be more broadly beneficial in applications where analysts would typically need to aggregate data over time, larger groups, or geography to produce statistically reliable estimates. The eMKF approach could be used in those cases to preserve the granularity of the data while improving the precision of the estimates.

Finally, no guidelines or recommendations for standards exist concerning the presentation of model-based estimates, unlike the current NCHS criteria for rate, count, and proportion standards for presentation (1,2). For example, some model-based estimates may have wide 95% CIs or large SEs (that is, greater than 30% relative standard error). Analysts will need to consider whether it is informative to present those estimates along with their associated uncertainty, or whether those estimates should be flagged or not shown.

## Conclusions

The eMKF offers substantial gains in estimate reliability and overall accuracy under a wide array of analytic scenarios commonly encountered by NCHS analysts. This tool can provide a relatively straightforward and exceptionally low-cost approach for generating more granular estimates of health outcomes for small subpopulations, compared with alternative approaches like oversampling or aggregating data.