# Results

## Simulation Scenario 1: Patterns by Group Size

Based on simulated quarterly NHIS data for 2019–2021 by age group and population subgroup, model-based estimates using eMKF BMA up to cubic trends and direct estimates for the three different sample size scenarios were compared with direct estimates from the total NHIS (which are assumed to be the true estimates or gold standard) for the prevalence of diagnosed diabetes and reported history of smoking.

Across all sample size scenarios, the eMKF BMA estimates presented marked improvements in accuracy, as indicated by RRMSEs all less than 1 for both diagnosed diabetes and history of smoking (Figure 1).

Figure 1 Relative root mean squared error of model-based estimates compared with direct estimates, by sample size of each age and population subgroup using simulated data: National Health Interview Survey, 2021, Quarter 4

NOTE: Each plotted point represents a distinct age and population subgroup for each outcome.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2021, Quarter 4.

Figure 1 is a dot plot of relative root mean squared error for model-based estimates of diagnosed diabetes and smoking history, by sample size using simulated data from National Health Interview Survey, Quarter 4.

In the large subsample (40% of NHIS data), RRMSEs for eMKF BMA estimates were 0.39 for diagnosed diabetes and 0.48 for history of smoking (Table B), on average across all of the age and population subgroups. Similar average RRMSEs were seen for the medium (0.44) and small (0.43) subsample size scenarios for diagnosed diabetes and reported history of smoking (0.47 for the medium subsample and 0.51 for the small subsample). These improvements in RMSE corresponded to large increases in equivalent sample size across the various subsample sizes. Average percentage increases in equivalent sample sizes of 174% (large subsample), 158% (medium subsample), and 174% (small subsample) were seen for diagnosed diabetes. Average increases were slightly smaller for smoking: 121% for the large subsample, 124% for the medium subsample, and 120% for the small subsample.

Table B Enhanced modified Kalman filter procedure performance across various subsample size simulation scenarios: National Health Interview Survey, 2021, Quarter 4

Characteristic | Diagnosed diabetes | | | Reported history of smoking
Characteristic | Large subsample | Medium subsample | Small subsample | Large subsample | Medium subsample | Small subsample
Average standardized difference between direct subsample estimate and true NHIS estimate | 0.02 | 0.01 | -0.76 | -0.08 | -0.16 | 0.13
Average standardized difference between model-based subsample estimate and true NHIS estimate | -0.44 | -0.79 | -1.39 | 0.26 | 0.01 | -0.28
Average RRMSE (RMSE_eMKF/RMSE_subsample) | 0.39 | 0.44 | 0.43 | 0.48 | 0.47 | 0.51
Average percent increase in equivalent sample size (%) | 174 | 158 | 174 | 121 | 124 | 120

NOTES: Estimates reflect averages of each metric across all age and population subgroups within each subsample size scenario and outcome. NHIS is National Health Interview Survey, RRMSE is relative root mean squared error, and eMKF is enhanced modified Kalman filter. The large subsample was 40% of the total NHIS sample, the medium subsample was 20% of the total, and the small subsample was 10%. The true NHIS estimates were calculated using the total NHIS sample.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2021, Quarter 4.

The average standardized differences between the model-based estimates and the gold-standard (true) NHIS estimates from the total sample ranged in absolute value from about zero to 1.39. For diagnosed diabetes, the average standardized differences between the true NHIS direct estimates and the model-based estimates across all the age and population subgroups were –0.44 for the large subsample, –0.79 for the medium subsample, and –1.39 for the small subsample. By comparison, the average standardized differences between the direct estimates of diagnosed diabetes for the true NHIS and the simulated subsample direct estimates were about zero for the large and medium scenarios and –0.76 for the small subsample. For reported history of smoking, the average standardized differences for the model-based estimates varied from –0.28 to 0.26, compared with –0.16 to 0.13 for the direct subsample estimates, indicating that the standardized differences between the direct subsample and model-based estimates, relative to the true NHIS direct estimates, were generally similar in absolute magnitude. Larger average standardized differences were generally seen for smaller sample sizes, with both the eMKF BMA model-based estimates and the subsample direct estimates having smaller standardized differences from the true NHIS direct estimates as sample size increased.

Comparisons across these metrics by specific age and population subgroup and outcome can be seen in Tables C and D. Figures 2 and 3 illustrate the model-based estimates, direct subsample estimates, and corresponding 95% CIs relative to the true estimates for adults age 65 and older (Figure 2) and adults ages 18–49 (Figure 3). Patterns for other age groups were very similar and consequently are not shown.

Table C Simulated subsample sizes, prevalence of diagnosed diabetes, and 95% confidence interval: National Health Interview Survey, 2021 Quarter 4

Age group and race and ethnicity | Sample size | True estimate | Sample direct estimate | | | | Model-based estimate | | | | RRMSE^5^ | Percent increase in equivalent sample size
Age group and race and ethnicity | Sample size | True estimate | Direct estimate | Standard error | Standardized difference^1^ | 95% confidence interval^2^ | Model-based estimate | RMSE^3^ | Standardized difference | 95% confidence interval^4^ | RRMSE^5^ | Percent increase in equivalent sample size
18–49 | Large subsample (40%)
Non-Hispanic:
Black | 137 | 3.7 | 5.5 | 2.2 | 1.6 | 2.1–11.5 | 4.5 | 0.7 | 0.7 | 3.1–5.8 | 0.3 | 214.3
White | 746 | 2.9 | 2.5 | 0.6 | -0.9 | 1.4–4.0 | 2.4 | 0.4 | -1.1 | 1.6–3.2 | 0.7 | 50.0
Other or multiple race | 157 | 3.0 | 4.1 | 2.7 | 0.8 | 0.6–13.1 | 1.7 | 0.7 | -1.0 | 0.2–3.1 | 0.3 | 285.7
Hispanic | 276 | 3.3 | 3.7 | 1.2 | 0.6 | 1.7–6.9 | 4.0 | 0.6 | 1.0 | 2.9–5.2 | 0.5 | 100.0
50–64
Non-Hispanic:
Black | 91 | 19.6 | 18.5 | 4.6 | -0.3 | 10.3–29.4 | 18.0 | 1.5 | -0.5 | 15.0–21.0 | 0.3 | 206.7
White | 515 | 11.7 | 10.0 | 1.5 | -1.5 | 7.3–13.4 | 10.8 | 0.8 | -0.8 | 9.3–12.3 | 0.5 | 87.5
Other or multiple race | 58 | 14.9 | 16.1 | 5.5 | 0.3 | 6.9–30.1 | 13.3 | 1.7 | -0.5 | 9.9–16.7 | 0.3 | 223.5
Hispanic | 94 | 19.2 | 21.3 | 5.3 | 0.7 | 11.7–33.9 | 18.1 | 1.7 | -0.3 | 14.9–21.4 | 0.3 | 211.8
65 and older
Non-Hispanic:
Black | 85 | 35.2 | 31.8 | 5.7 | -0.9 | 21.0–44.3 | 27.7 | 1.9 | -1.9 | 24.0–31.5 | 0.3 | 200.0
White | 732 | 16.5 | 17.0 | 1.6 | 0.5 | 14.0–20.3 | 17.0 | 0.8 | 0.6 | 15.4–18.7 | 0.5 | 100.0
Other or multiple race | 52 | 24.5 | 24.1 | 6.4 | -0.1 | 12.6–39.3 | 26.0 | 2.3 | 0.4 | 21.5–30.6 | 0.4 | 178.3
Hispanic | 76 | 33.9 | 31.8 | 7.2 | -0.5 | 18.2–48.1 | 26.6 | 2.2 | -1.7 | 22.3–30.9 | 0.3 | 227.3
18–49 | Medium subsample (20%)
Non-Hispanic:
Black | 67 | 3.7 | 5.2 | 3.4 | 1.3 | 0.7–16.8 | 3.6 | 1.1 | -0.1 | 1.5–5.7 | 0.3 | 209.1
White | 378 | 2.9 | 2.5 | 0.9 | -0.9 | 1.1–4.9 | 2.4 | 0.6 | -1.1 | 1.2–3.6 | 0.7 | 50.0
Other or multiple race | 77 | 3.0 | 1.2 | 1.2 | -1.3 | 0.0–7.1 | 1.7 | 0.8 | -0.9 | 0.2–3.3 | 0.7 | 50.0
Hispanic | 135 | 3.3 | 4.2 | 1.8 | 1.3 | 1.4–9.3 | 3.9 | 0.9 | 0.8 | 2.2–5.6 | 0.5 | 100.0
50–64
Non-Hispanic:
Black | 47 | 19.6 | 17.2 | 7.3 | -0.7 | 5.5–36.7 | 17.3 | 2.2 | -0.7 | 13.0–21.7 | 0.3 | 231.8
White | 258 | 11.7 | 7.3 | 1.7 | -4.0 | 4.3–11.3 | 9.6 | 1.2 | -2.0 | 7.2–11.9 | 0.7 | 41.7
Other or multiple race | 31 | 14.9 | 19.4 | 8.3 | 1.3 | 6.1–41.2 | 11.9 | 2.3 | -0.9 | 7.3–16.4 | 0.3 | 260.9
Hispanic | 47 | 19.2 | 17.1 | 5.0 | -0.7 | 8.4–29.4 | 17.3 | 2.2 | -0.6 | 13.1–21.5 | 0.4 | 127.3
65 and older
Non-Hispanic:
Black | 42 | 35.2 | 41.7 | 9.1 | 1.7 | 24.0–61.2 | 27.9 | 2.6 | -1.9 | 22.7–33.0 | 0.3 | 250.0
White | 370 | 16.5 | 18.3 | 2.1 | 2.0 | 14.4–22.9 | 17.1 | 1.1 | 0.6 | 14.9–19.2 | 0.5 | 90.9
Other or multiple race | 26 | 24.5 | 16.8 | 7.0 | -1.7 | 5.1–36.5 | 20.6 | 2.8 | -0.9 | 15.2–26.0 | 0.4 | 150.0
Hispanic | 37 | 33.9 | 42.3 | 13.2 | 2.0 | 17.3–70.7 | 25.7 | 3.0 | -1.9 | 19.7–31.6 | 0.2 | 340.0
18–49 | Small subsample (10%)
Non-Hispanic:
Black | 33 | 3.7 | 6.2 | 5.3 | 2.2 | 0.3–26.3 | 4.3 | 1.1 | 0.6 | 2.2–6.5 | 0.2 | 381.8
White | 190 | 2.9 | 1.9 | 1.2 | -2.2 | 0.3–6.0 | 1.8 | 0.5 | -2.5 | 0.8–2.7 | 0.4 | 140.0
Other or multiple race | 40 | 3.0 | 2.2 | 2.2 | -0.6 | 0.0–12.3 | 1.8 | 0.8 | -0.9 | 0.3–3.3 | 0.4 | 175.0
Hispanic | 68 | 3.3 | 3.7 | 2.1 | 0.5 | 0.6–11.3 | 3.9 | 0.8 | 0.8 | 2.3–5.5 | 0.4 | 162.5
50–64
Non-Hispanic:
Black | 21 | 19.6 | 17.7 | 10.2 | -0.6 | 3.0–46.7 | 13.7 | 3.8 | -1.8 | 6.2–21.1 | 0.4 | 168.4
White | 131 | 11.7 | 5.0 | 2.2 | -6.1 | 1.7–11.2 | 6.9 | 1.9 | -4.4 | 3.1–10.7 | 0.9 | 15.8
Other or multiple race | 17 | 14.9 | 21.0 | 10.6 | 1.7 | 4.7–49.6 | 10.2 | 4.3 | -1.3 | 1.8–18.6 | 0.4 | 146.5
Hispanic | 25 | 19.2 | 11.5 | 6.2 | -2.5 | 2.5–30.0 | 14.1 | 3.5 | -1.6 | 7.2–20.9 | 0.6 | 77.1
65 and older
Non-Hispanic:
Black | 22 | 35.2 | 28.4 | 9.5 | -1.8 | 11.7–51.0 | 22.1 | 3.6 | -3.4 | 15.0–29.1 | 0.4 | 163.9
White | 187 | 16.5 | 18.0 | 3.0 | 1.6 | 12.5–24.6 | 17.7 | 1.8 | 1.3 | 14.2–21.2 | 0.6 | 66.7
Other or multiple race | 12 | 24.5 | 16.6 | 11.2 | -1.8 | 1.8–50.0 | 21.7 | 4.1 | -0.6 | 13.7–29.7 | 0.4 | 173.2
Hispanic | 19 | 33.9 | 35.1 | 22.3 | 0.3 | 3.1–84.0 | 22.0 | 4.3 | -2.8 | 13.6–30.4 | 0.2 | 418.6

0.0 Quantity more than zero but less than 0.05.

1 The standardized difference for the enhanced modified Kalman filter (eMKF) (model-based) or direct estimates is calculated as (eMKF or direct estimate minus true estimate) divided by true standard error (SE).

2 Korn–Graubard 95% confidence interval.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) SE. For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance tradeoff.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 Relative RMSE is calculated as the ratio: eMKF RMSE divided by direct RMSE.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2021, Quarter 4.

Table D Simulated subsample sizes, prevalence of smoking history, and 95% confidence interval: National Health Interview Survey, 2021, Quarter 4

Age group and race and ethnicity | Sample size | True estimate | Sample direct estimate | | | | Model-based estimate | | | | RRMSE^5^ | Percent increase in equivalent sample size
Age group and race and ethnicity | Sample size | True estimate | Direct estimate | Standard error | Standardized difference^1^ | 95% confidence interval^2^ | Model-based estimate | RMSE^3^ | Standardized difference | 95% confidence interval^4^ | RRMSE^5^ | Percent increase in equivalent sample size
18–49 | Large subsample (40%)
Non-Hispanic:
Black | 137 | 19.8 | 18.0 | 3.8 | -1.6 | 11.1–26.8 | 19.6 | 2.1 | -0.1 | 15.5–23.7 | 0.6 | 81.0
White | 746 | 31.9 | 33.6 | 2.0 | 3.6 | 29.6–37.8 | 34.0 | 1.5 | 1.5 | 31.0–36.9 | 0.8 | 33.3
Other or multiple race | 157 | 17.2 | 23.2 | 4.2 | 4.2 | 15.4–32.7 | 23.8 | 2.2 | 2.8 | 19.5–28.1 | 0.5 | 90.9
Hispanic | 276 | 19.7 | 20.2 | 3.1 | 0.8 | 14.5–27.0 | 19.6 | 1.9 | 0.0 | 15.9–23.3 | 0.6 | 63.2
50–64
Non-Hispanic:
Black | 91 | 27.2 | 25.3 | 5.1 | -0.6 | 15.8–36.8 | 32.1 | 2.1 | 1.4 | 28.0–36.2 | 0.4 | 142.9
White | 515 | 45.3 | 47.4 | 2.6 | 1.9 | 42.1–52.7 | 46.2 | 1.3 | 0.6 | 43.6–48.8 | 0.5 | 100.0
Other or multiple race | 58 | 25.1 | 18.2 | 4.7 | -2.0 | 9.4–30.3 | 27.4 | 2.3 | 0.6 | 22.8–32.0 | 0.5 | 104.3
Hispanic | 94 | 35.1 | 35.2 | 5.9 | 0.0 | 23.8–48.0 | 28.8 | 2.1 | -1.8 | 24.7–33.0 | 0.4 | 181.0
65 and older
Non-Hispanic:
Black | 85 | 41.2 | 39.1 | 7.0 | -0.5 | 25.5–54.1 | 40.5 | 2.2 | -0.2 | 36.1–44.8 | 0.3 | 218.2
White | 732 | 47.6 | 47.8 | 2.2 | 0.2 | 43.5–52.2 | 49.3 | 1.2 | 1.2 | 47.0–51.6 | 0.6 | 83.3
Other or multiple race | 52 | 38.0 | 29.7 | 7.4 | -1.9 | 16.1–46.6 | 26.7 | 2.4 | -2.1 | 22.0–31.4 | 0.3 | 208.3
Hispanic | 76 | 37.3 | 31.1 | 6.0 | -1.4 | 19.8–44.5 | 34.0 | 2.4 | -0.7 | 29.4–38.7 | 0.4 | 150.0
18–49 | Medium subsample (20%)
Non-Hispanic:
Black | 67 | 19.8 | 18.3 | 6.5 | -1.3 | 7.4–34.9 | 19.6 | 2.3 | -0.1 | 15.2–24.1 | 0.4 | 182.6
White | 378 | 31.9 | 37.3 | 3.0 | 11.6 | 31.4–43.6 | 34.5 | 1.8 | 1.9 | 31.0–37.9 | 0.6 | 66.7
Other or multiple race | 77 | 17.2 | 23.3 | 5.8 | 4.3 | 12.9–36.8 | 23.4 | 2.4 | 2.7 | 18.8–28.0 | 0.4 | 141.7
Hispanic | 135 | 19.7 | 23.7 | 4.8 | 5.8 | 14.8–34.6 | 19.3 | 2.0 | -0.2 | 15.3–23.2 | 0.4 | 140.0
50–64
Non-Hispanic:
Black | 47 | 27.2 | 31.2 | 8.9 | 1.2 | 15.0–51.7 | 31.9 | 3.0 | 1.3 | 26.1–37.7 | 0.3 | 196.7
White | 258 | 45.3 | 44.5 | 3.8 | -0.7 | 36.9–52.2 | 45.5 | 1.9 | 0.1 | 41.7–49.2 | 0.5 | 100.0
Other or multiple race | 31 | 25.1 | 14.2 | 6.2 | -3.1 | 4.4–31.5 | 24.1 | 3.2 | -0.3 | 17.8–30.3 | 0.5 | 93.8
Hispanic | 47 | 35.1 | 31.4 | 7.5 | -1.2 | 17.5–48.3 | 26.3 | 2.9 | -2.5 | 20.5–32.0 | 0.4 | 158.6
65 and older
Non-Hispanic:
Black | 42 | 41.2 | 46.8 | 9.5 | 1.5 | 27.7–66.5 | 42.1 | 3.9 | 0.2 | 34.5–49.7 | 0.4 | 143.6
White | 370 | 47.6 | 46.8 | 3.1 | -0.9 | 40.6–53.0 | 48.6 | 2.2 | 0.7 | 44.2–52.9 | 0.7 | 40.9
Other or multiple race | 26 | 38.0 | 15.4 | 8.9 | -5.1 | 2.7–41.5 | 23.4 | 4.0 | -2.8 | 15.6–31.3 | 0.5 | 122.5
Hispanic | 37 | 37.3 | 21.6 | 8.1 | -3.7 | 8.0–42.0 | 32.5 | 4.0 | -1.1 | 24.7–40.3 | 0.5 | 102.5
18–49 | Small subsample (10%)
Non-Hispanic:
Black | 33 | 19.8 | 10.7 | 8.4 | -8.0 | 0.7–39.1 | 16.8 | 2.9 | -1.2 | 11.1–22.5 | 0.4 | 189.7
White | 190 | 31.9 | 40.1 | 4.3 | 17.4 | 31.6–49.0 | 35.6 | 2.5 | 2.8 | 30.7–40.5 | 0.6 | 72.0
Other or multiple race | 40 | 17.2 | 29.5 | 8.7 | 8.5 | 13.8–49.7 | 23.5 | 3.2 | 2.7 | 17.2–29.7 | 0.4 | 171.9
Hispanic | 68 | 19.7 | 21.0 | 5.7 | 2.0 | 10.9–34.7 | 19.6 | 2.6 | 0.0 | 14.5–24.6 | 0.5 | 119.2
50–64
Non-Hispanic:
Black | 21 | 27.2 | 29.1 | 13.1 | 0.6 | 7.5–61.2 | 34.3 | 4.2 | 2.0 | 26.0–42.5 | 0.3 | 211.9
White | 131 | 45.3 | 45.2 | 5.3 | -0.1 | 34.6–56.1 | 45.5 | 2.6 | 0.1 | 40.4–50.6 | 0.5 | 103.8
Other or multiple race | 17 | 25.1 | 5.7 | 3.5 | -5.5 | 0.2–26.6 | 11.7 | 2.9 | -3.3 | 5.9–17.4 | 0.8 | 20.7
Hispanic | 25 | 35.1 | 28.6 | 12.2 | -2.1 | 8.2–58.5 | 24.8 | 4.0 | -2.9 | 17.0–32.7 | 0.3 | 205.0
65 and older
Non-Hispanic:
Black | 22 | 41.2 | 54.2 | 11.3 | 3.4 | 30.5–76.5 | 38.9 | 5.6 | -0.5 | 28.0–49.8 | 0.5 | 101.8
White | 187 | 47.6 | 48.5 | 4.1 | 0.9 | 40.2–56.9 | 48.8 | 3.1 | 0.8 | 42.7–54.8 | 0.8 | 32.3
Other or multiple race | 12 | 38.0 | 5.8 | 5.8 | -7.3 | 0.0–37.0 | 13.8 | 4.5 | -4.6 | 5.1–22.6 | 0.8 | 28.9
Hispanic | 19 | 37.3 | 44.4 | 17.3 | 1.7 | 12.6–80.1 | 40.4 | 6.1 | 0.7 | 28.4–52.4 | 0.4 | 183.6

0.0 Quantity more than zero but less than 0.05.

1 The standardized difference for the enhanced model Kalman filter (eMKF) (model-based) or direct estimates is calculated as: (eMKF or direct estimate minus true estimate) divided by true standard error (SE).

2 Korn–Graubard 95% confidence interval.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) SE. For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 Relative RMSE (RRMSE) is calculated as the ratio: eMKF RMSE divided by direct RMSE.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2021, Quarter 4.

Figure 2 Direct and model-based estimates of prevalence of diagnosed diabetes and 95% confidence intervals for adults age 65 and older, by simulated sample size, race and ethnicity, and quarter: National Health Interview Survey, 2019–2021

NOTES: NHIS is National Health Interview Survey; CI is confidence interval. The small subsample is 10% of the total NHIS sample, the medium subsample is 20%, and the large subsample is 40%. The true NHIS estimates were calculated using the total NHIS sample for each quarter and survey year.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2019–2021.

Figure 2 is a series of bar plots showing true, direct, and model-based estimates of diagnosed diabetes for age 65 and older, by race and ethnicity and simulated sample size using simulated data from National Health Interview Survey, 2019 through 2021, each quarter.

Figure 3 Direct and model-based estimates of prevalence of reported ever smoking 100 cigarettes or more and 95% confidence intervals for adults ages 18–49, by simulated sample size, race and ethnicity, and quarter: National Health Interview Survey, 2019–2021

NOTES: NHIS is National Health Interview Survey; CI is confidence interval. The small subsample is 10% of the total NHIS sample, the medium subsample is 20%, and the large subsample is 40%. The true NHIS estimates were calculated using the total NHIS sample for each quarter and survey year.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2019–2021.

Figure 3 is a series of bar plots showing true, direct, and model-based estimates of ever smoking 100 cigarettes or more for ages 18 through 49, by race and ethnicity and simulated sample size using simulated data from National Health Interview Survey, 2019 through 2021, each quarter.

The largest gains in RMSE and equivalent sample size were generally seen for the smallest subgroups, where direct estimates would typically not meet NCHS data presentation standards. For example, when subsample sizes were smaller than 50, increases in equivalent sample sizes of 77%–419% were observed for estimates of diagnosed diabetes prevalence among Hispanic, Black, and other or multiple race persons (Table C). In contrast, for the largest racial and ethnic group, White, where the direct estimates typically meet data presentation standards, increases in equivalent sample size were generally smaller (about 15%–140% for diagnosed diabetes and 32%–104% for history of smoking) (Table D). These patterns can also be seen in Figures 2 and 3, where direct and model-based estimates of diagnosed diabetes and history of smoking, along with 95% CIs, are very similar for the White category. In contrast, the model-based 95% CIs for other racial and ethnic groups are narrower than the direct estimate 95% CIs across both outcomes and all subsample size scenarios.

## Simulation Scenario 2: Patterns by Trend Form

### Common Trends by Group

Based on simulated trends in obesity and severe obesity by population group derived from NHANES data, model-based estimates using eMKF BMA up to cubic trends were compared with direct estimates across the three different trend scenarios.

Across all simulation scenarios, the eMKF BMA estimates presented marked improvements in overall accuracy, as indicated by RRMSE values less than 1 for obesity and severe obesity (Figures 4 and 5, Table E). On average, RRMSE values were 0.63–0.90 compared with direct estimates. These values corresponded to a 12% to 69% increase in equivalent sample size when trends were simulated to be common across groups. Generally, improvements in accuracy (lower RRMSEs) were smaller for cubic trends than linear trends. The absolute value of the average standardized differences between the model-based and direct estimates were generally less than 0.5 for all trend scenarios and outcomes, indicating that model-based estimates were within 0.5 SE of direct estimates.

Figure 4 Relative root mean squared error of model-based estimates compared with direct estimates, by sample size and population group using simulated data assuming common trends in obesity outcomes: National Health and Nutrition Examination Survey, 2017–March 2020

NOTES: Linear, quadratic, and cubic trends are simulated. Obesity is defined as a body mass index greater than or equal to 30 kg/m^2^ and severe obesity as a body mass index greater than or equal to 40 kg/m^2^.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 2017–March 2020.

Figure 4 is a set of dot plots showing relative root mean squared error for model-based estimates of obesity and severe obesity in linear, quadratic, and cubic trend forms, by sample size using simulated data assuming common trends, from National Health and Nutrition Examination Survey, 2017 through March 2020.

Figure 5 Relative root mean squared error of model-based estimates compared with direct estimates, by sample size and population subgroup using simulated data assuming unique trends in obesity outcomes: National Health and Nutrition Examination Survey, 2017–March 2020

NOTES: Linear, quadratic, and cubic trends are simulated. Obesity is defined as a body mass index greater than or equal to 30 kg/m^2^ and severe obesity as a body mass index greater than or equal to 40 kg/m^2^.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 2017–March 2020.

Figure 5 is a set of dot plots showing relative root mean squared error for model-based estimates of obesity and severe obesity in linear, quadratic, and cubic trend forms, by sample size using simulated data assuming unique trends, from National Health and Nutrition Examination Survey, 2017 through March 2020.

Table E Enhanced modified Kalman filter procedure performance across various trend simulation scenarios: National Health and Nutrition Examination Survey, 1999–March 2020

Characteristic | Obesity | | | Severe obesity
Characteristic | Linear | Quadratic | Cubic | Linear | Quadratic | Cubic
| Common trends
Average standardized difference | 0.3 | 0.5 | 0.2 | -0.2 | 0.4 | -0.1
Average relative root mean squared error | 0.66 | 0.72 | 0.90 | 0.71 | 0.63 | 0.86
Average increase in equivalent sample size (%) | 60.0 | 46.0 | 12.0 | 45.0 | 69.0 | 17.0
| Unique trends
Average standardized difference | -0.1 | 0.1 | 0.4 | -0.5 | -0.1 | 0.2
Average relative root mean squared error | 0.84 | 0.87 | 0.92 | 0.80 | 0.85 | 0.89
Average increase in equivalent sample size (%) | 21.0 | 15.0 | 9.0 | 27.0 | 19.0 | 14.0

NOTES: Estimates reflect averages of each metric across all of the population subgroups within each trend form scenario and outcome. Obesity is defined as a body mass index greater than or equal to 30 kg/m^2^, and severe obesity as a body mass index greater than or equal to 40 kg/m^2^. Standardized differences were calculated as the difference between the model-based and direct estimate, divided by the direct estimate standard error.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–March 2020.

### Unique Trends by Group

When the slopes of the trends were simulated to be unique by demographic subgroup, average RRMSEs were larger than when trends were shared across groups. When trends were unique by group, average RRMSEs ranged from 0.80 to 0.92, with corresponding increases in equivalent sample size of 9%–27%. Similarly, increases in equivalent sample size were smaller than when trends were shared. In both cases, improvements were smaller for cubic trends than for linear or quadratic trends.

Comparisons across these metrics by demographic subgroup and outcome can be seen in Tables F–J. Across both outcomes, temporal trends in eMKF BMA estimates aligned very closely with the simulated trend forms for all population subgroups (Figures 6–9).

Table F Comparison of direct estimates to enhanced modified Kalman filter-based estimates for simulated trends in the prevalence of obesity, by age group and race and ethnicity where trends are common across group: National Health and Nutrition Examination Survey, 1999–March 2020

Age group and race and ethnicity | Sample size | Direct estimate | Standard error | 95% confidence interval^1^ | Model-based estimate | RMSE^2^ | 95% confidence interval^3^ | Standardized difference^4^ | RRMSE^5^ | Percent increase in equivalent sample size
18–24 | Linear
Non-Hispanic:
Black | 268 | 50.1 | 3.6 | 42.9–57.3 | 54.0 | 2.0 | 50.1–57.8 | 1.1 | 0.6 | 80.5
White | 349 | 51.2 | 2.6 | 45.9–56.6 | 50.2 | 1.7 | 46.9–53.5 | -0.4 | 0.7 | 52.6
Other or multiple race | 196 | 48.4 | 5.4 | 37.4–59.6 | 47.3 | 2.5 | 42.3–52.2 | -0.2 | 0.5 | 115.2
Mexican American | 183 | 54.9 | 5.3 | 43.9–65.6 | 51.7 | 2.1 | 47.5–55.9 | -0.6 | 0.4 | 149.4
Other Hispanic | 150 | 51.3 | 3.3 | 43.1–59.6 | 48.2 | 2.1 | 44.0–52.4 | -1.0 | 0.7 | 52.6
25–44
Non-Hispanic:
Black | 761 | 64.1 | 1.7 | 60.6–67.5 | 66.0 | 1.5 | 63.1–68.9 | 1.1 | 0.9 | 13.1
White | 828 | 59.1 | 1.4 | 55.7–62.5 | 59.3 | 1.2 | 57.0–61.6 | 0.1 | 0.8 | 22.7
Other or multiple race | 571 | 50.6 | 3.2 | 44.2–57.1 | 52.3 | 2.0 | 48.4–56.1 | 0.5 | 0.6 | 63.1
Mexican American | 398 | 63.9 | 2.6 | 58.5–69.1 | 63.8 | 1.7 | 60.5–67.1 | -0.1 | 0.6 | 56.0
Other Hispanic | 289 | 54.6 | 4.0 | 46.3–62.7 | 60.5 | 2.2 | 56.1–64.8 | 1.5 | 0.6 | 81.2
45–64
Non-Hispanic:
Black | 962 | 68.9 | 2.5 | 63.6–73.8 | 70.4 | 2.0 | 66.4–74.3 | 0.6 | 0.8 | 25.2
White | 977 | 65.7 | 1.7 | 62.1–69.1 | 65.0 | 1.5 | 62.0–68.0 | -0.4 | 0.9 | 14.8
Other or multiple race | 614 | 52.2 | 3.3 | 45.6–58.7 | 54.4 | 2.4 | 49.7–59.2 | 0.7 | 0.8 | 34.2
Mexican American | 391 | 62.9 | 2.2 | 57.9–67.7 | 64.3 | 1.9 | 60.6–68.0 | 0.6 | 0.9 | 18.3
Other Hispanic | 345 | 57.6 | 3.8 | 49.6–65.2 | 59.1 | 2.5 | 54.1–64.0 | 0.4 | 0.7 | 52.2
65 and older
Non-Hispanic:
Black | 564 | 65.1 | 2.7 | 59.6–70.3 | 67.1 | 1.6 | 63.9–70.3 | 0.8 | 0.6 | 63.3
White | 1,216 | 59.6 | 1.9 | 55.7–63.4 | 60.5 | 1.4 | 57.8–63.1 | 0.5 | 0.7 | 41.9
Other or multiple race | 265 | 40.0 | 3.7 | 32.7–47.6 | 46.1 | 2.2 | 41.7–50.5 | 1.7 | 0.6 | 65.0
Mexican American | 159 | 60.9 | 3.7 | 52.8–68.5 | 63.5 | 1.8 | 60.0–67.1 | 0.7 | 0.5 | 105.7
Other Hispanic | 207 | 68.7 | 3.7 | 60.8–76.0 | 64.7 | 2.0 | 60.7–68.7 | -1.1 | 0.6 | 83.1
18–24 | Quadratic
Non-Hispanic:
Black | 268 | 45.0 | 4.0 | 37.0–53.3 | 51.2 | 2.7 | 45.9–56.5 | 1.5 | 0.7 | 48.4
White | 349 | 44.4 | 2.5 | 39.1–49.8 | 46.3 | 2.0 | 42.4–50.2 | 0.8 | 0.8 | 27.2
Other or multiple race | 196 | 39.0 | 5.7 | 27.8–51.1 | 44.6 | 3.0 | 38.7–50.4 | 1.0 | 0.5 | 91.6
Mexican American | 183 | 46.1 | 6.4 | 33.2–59.5 | 49.7 | 2.7 | 44.5–55.0 | 0.6 | 0.4 | 140.8
Other Hispanic | 150 | 42.0 | 3.6 | 34.0–50.4 | 44.6 | 2.4 | 40.0–49.3 | 0.7 | 0.7 | 50.6
25–44
Non-Hispanic:
Black | 761 | 58.5 | 1.5 | 54.9–62.0 | 59.0 | 1.3 | 56.5–61.4 | 0.3 | 0.9 | 15.2
White | 828 | 50.5 | 1.8 | 47.0–54.0 | 50.8 | 1.4 | 48.1–53.6 | 0.2 | 0.8 | 25.4
Other or multiple race | 571 | 44.0 | 3.0 | 38.1–50.0 | 44.6 | 2.0 | 40.7–48.5 | 0.2 | 0.7 | 49.5
Mexican American | 398 | 54.1 | 2.5 | 49.0–59.1 | 54.6 | 1.8 | 51.1–58.0 | 0.2 | 0.7 | 42.9
Other Hispanic | 289 | 47.1 | 3.8 | 39.5–54.8 | 52.0 | 2.3 | 47.4–56.6 | 1.3 | 0.6 | 62.2
45–64
Non-Hispanic:
Black | 962 | 62.1 | 2.4 | 57.3–66.8 | 63.2 | 2.1 | 59.2–67.3 | 0.5 | 0.9 | 14.0
White | 977 | 58.7 | 1.7 | 55.3–62.0 | 58.2 | 1.7 | 55.0–61.4 | -0.3 | 1.0 | 2.5
Other or multiple race | 614 | 46.3 | 3.8 | 38.6–54.1 | 48.1 | 2.9 | 42.3–53.9 | 0.5 | 0.8 | 30.0
Mexican American | 391 | 55.9 | 2.3 | 50.9–60.9 | 57.0 | 2.0 | 53.0–60.9 | 0.5 | 0.9 | 12.7
Other Hispanic | 345 | 50.4 | 3.5 | 43.4–57.3 | 51.9 | 2.7 | 46.5–57.2 | 0.4 | 0.8 | 26.1
65 and older
Non-Hispanic:
Black | 564 | 57.2 | 2.8 | 51.4–62.8 | 58.3 | 2.0 | 54.5–62.2 | 0.4 | 0.7 | 43.6
White | 1,216 | 52.1 | 2.0 | 48.2–56.0 | 52.5 | 1.6 | 49.5–55.6 | 0.2 | 0.8 | 25.2
Other or multiple race | 265 | 33.8 | 4.3 | 25.4–43.0 | 38.7 | 2.6 | 33.6–43.8 | 1.1 | 0.6 | 66.0
Mexican American | 159 | 56.5 | 3.4 | 48.4–64.4 | 56.1 | 2.1 | 52.0–60.3 | -0.1 | 0.6 | 59.1
Other Hispanic | 207 | 60.2 | 4.7 | 50.4–69.5 | 56.4 | 2.6 | 51.3–61.6 | -0.8 | 0.6 | 78.1
18–24 | Cubic
Non-Hispanic:
Black | 268 | 35.8 | 3.9 | 28.2–44.0 | 38.5 | 3.6 | 31.5–45.5 | 0.7 | 0.9 | 9.4
White | 349 | 36.6 | 3.5 | 29.7–44.0 | 36.9 | 3.1 | 30.8–42.9 | 0.1 | 0.9 | 14.1
Other or multiple race | 196 | 33.8 | 5.6 | 22.9–46.0 | 33.5 | 4.1 | 25.4–41.6 | -0.1 | 0.7 | 36.4
Mexican American | 183 | 37.9 | 5.9 | 26.4–50.5 | 36.8 | 4.2 | 28.5–45.0 | -0.2 | 0.7 | 40.0
Other Hispanic | 150 | 35.3 | 4.1 | 27.2–44.0 | 34.7 | 3.4 | 28.0–41.3 | -0.2 | 0.8 | 21.3
25–44
Non-Hispanic:
Black | 761 | 49.3 | 1.6 | 45.7–52.9 | 49.5 | 1.6 | 46.4–52.6 | 0.1 | 1.0 | 2.3
White | 828 | 43.2 | 1.5 | 39.8–46.7 | 43.3 | 1.4 | 40.4–46.1 | 0.1 | 1.0 | 2.2
Other or multiple race | 571 | 36.7 | 3.0 | 30.9–42.9 | 36.7 | 2.7 | 31.3–42.0 | 0.0 | 0.9 | 9.0
Mexican American | 398 | 43.6 | 2.5 | 38.6–48.7 | 44.2 | 2.4 | 39.5–48.9 | 0.2 | 1.0 | 5.5
Other Hispanic | 289 | 39.3 | 3.6 | 32.3–46.7 | 40.9 | 3.3 | 34.5–47.3 | 0.4 | 0.9 | 8.8
45–64
Non-Hispanic:
Black | 962 | 52.4 | 2.0 | 48.3–56.4 | 52.9 | 2.0 | 49.0–56.7 | 0.2 | 1.0 | 3.7
White | 977 | 48.5 | 1.7 | 45.0–52.0 | 48.4 | 1.7 | 45.1–51.7 | -0.1 | 1.0 | 3.8
Other or multiple race | 614 | 36.6 | 4.0 | 28.8–45.0 | 37.5 | 3.5 | 30.6–44.3 | 0.2 | 0.9 | 14.2
Mexican American | 391 | 48.4 | 2.9 | 42.6–54.3 | 48.5 | 2.7 | 43.2–53.7 | 0.0 | 0.9 | 8.8
Other Hispanic | 345 | 41.8 | 3.0 | 35.8–48.0 | 42.2 | 2.8 | 36.8–47.6 | 0.1 | 0.9 | 10.0
65 and older
Non-Hispanic:
Black | 564 | 47.5 | 3.2 | 41.1–54.0 | 49.5 | 3.1 | 43.4–55.6 | 0.6 | 1.0 | 3.4
White | 1,216 | 44.5 | 1.7 | 41.2–47.8 | 44.8 | 1.7 | 41.5–48.0 | 0.2 | 1.0 | 0.9
Other or multiple race | 265 | 26.1 | 3.7 | 19.1–34.1 | 28.9 | 3.5 | 22.0–35.8 | 0.8 | 1.0 | 4.7
Mexican American | 159 | 48.6 | 4.1 | 40.3–57.0 | 49.6 | 3.5 | 42.8–56.4 | 0.2 | 0.8 | 18.7
Other Hispanic | 207 | 51.7 | 4.3 | 42.9–60.5 | 51.6 | 3.5 | 44.7–58.4 | 0.0 | 0.8 | 23.9

0.0 Quantity more than zero but less than 0.05.

1 Korn–Graubard 95% confidence interval.

2 Root mean squared error (RMSE) is the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

3 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

4 The standardized difference between the enhanced modified Kalman filter (eMKF) (model-based) and direct estimates is calculated as: (eMKF estimate minus direct estimate) divided by direct SE.

5 Relative RMSE (RRMSE) is calculated as the ratio: eMKF RMSE divided by direct RMSE.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–March 2020.

Table G Comparison of direct estimates to enhanced modified Kalman filter-based estimates for simulated trends in the prevalence of severe obesity, by age group and race and ethnicity where trends are common across group: National Health and Nutrition Examination Survey, 1999–March 2020

Age group and race and ethnicity | Sample size | Direct estimate | Standard error | 95% confidence interval^1^ | Model-based estimate | RMSE^2^ | 95% confidence interval^3^ | Standardized difference^4^ | RRMSE^5^ | Percent increase in equivalent sample size
18–24 | Linear
Non-Hispanic:
Black | 268 | 20.3 | 4.5 | 12.2–30.7 | 18.6 | 2.3 | 14.1–23.1 | -0.4 | 0.5 | 93.8
White | 349 | 13.6 | 1.8 | 10.2–17.7 | 14.4 | 1.5 | 11.5–17.3 | 0.4 | 0.8 | 21.2
Other or multiple race | 196 | 12.9 | 3.7 | 6.5–22.2 | 13.2 | 2.2 | 9.0–17.5 | 0.1 | 0.6 | 72.0
Mexican American | 183 | 15.0 | 2.6 | 10.1–21.0 | 15.5 | 1.8 | 11.9–19.1 | 0.2 | 0.7 | 40.0
Other Hispanic | 150 | 17.4 | 4.4 | 9.6–27.8 | 15.5 | 2.3 | 10.9–20.0 | -0.4 | 0.5 | 88.4
25–44
Non-Hispanic:
Black | 761 | 30.6 | 1.6 | 27.3–34.0 | 30.3 | 1.2 | 27.9–32.7 | -0.1 | 0.8 | 32.6
White | 828 | 24.9 | 1.5 | 22.0–28.0 | 24.7 | 1.2 | 22.5–27.0 | -0.1 | 0.8 | 26.7
Other or multiple race | 571 | 19.0 | 2.4 | 14.5–24.2 | 20.1 | 1.6 | 17.0–23.2 | 0.5 | 0.7 | 50.8
Mexican American | 398 | 27.5 | 2.2 | 23.2–32.2 | 27.2 | 1.4 | 24.4–29.9 | -0.2 | 0.6 | 59.0
Other Hispanic | 289 | 24.0 | 2.8 | 18.6–30.1 | 23.8 | 1.6 | 20.7–26.9 | -0.1 | 0.6 | 78.3
45–64
Non-Hispanic:
Black | 962 | 33.6 | 1.5 | 30.6–36.7 | 33.1 | 1.3 | 30.6–35.6 | -0.4 | 0.9 | 15.7
White | 977 | 29.8 | 2.0 | 25.9–33.9 | 28.1 | 1.6 | 24.9–31.2 | -0.8 | 0.8 | 25.5
Other or multiple race | 614 | 17.8 | 3.3 | 11.7–25.4 | 19.3 | 2.0 | 15.3–23.3 | 0.5 | 0.6 | 63.1
Mexican American | 391 | 29.7 | 2.1 | 25.2–34.5 | 28.4 | 1.6 | 25.2–31.5 | -0.6 | 0.8 | 28.7
Other Hispanic | 345 | 24.4 | 2.6 | 19.3–30.0 | 24.3 | 1.8 | 20.7–27.9 | 0.0 | 0.7 | 42.5
65 and older
Non-Hispanic:
Black | 564 | 28.6 | 2.2 | 24.3–33.3 | 27.9 | 1.8 | 24.3–31.4 | -0.3 | 0.8 | 23.4
White | 1,216 | 25.6 | 1.5 | 22.7–28.8 | 25.0 | 1.4 | 22.3–27.7 | -0.4 | 0.9 | 12.1
Other or multiple race | 265 | 14.5 | 2.9 | 9.3–21.2 | 16.0 | 2.2 | 11.8–20.3 | 0.5 | 0.8 | 32.7
Mexican American | 159 | 24.7 | 2.7 | 18.2–32.2 | 24.8 | 2.1 | 20.7–28.8 | 0.0 | 0.8 | 31.6
Other Hispanic | 207 | 32.2 | 3.8 | 24.8–40.4 | 27.2 | 2.5 | 22.3–32.2 | -1.3 | 0.7 | 51.8
18–24 | Quadratic
Non-Hispanic:
Black | 268 | 16.5 | 3.6 | 10.0–25.0 | 16.9 | 2.3 | 12.4–21.3 | 0.1 | 0.6 | 59.8
White | 349 | 10.1 | 1.8 | 6.8–14.3 | 11.3 | 1.6 | 8.2–14.4 | 0.7 | 0.9 | 15.1
Other or multiple race | 196 | 11.1 | 3.1 | 5.7–19.0 | 11.3 | 2.1 | 7.1–15.5 | 0.1 | 0.7 | 48.1
Mexican American | 183 | 10.1 | 1.7 | 6.1–15.4 | 11.2 | 1.5 | 8.3–14.1 | 0.7 | 0.9 | 11.4
Other Hispanic | 150 | 14.1 | 3.7 | 7.7–23.0 | 13.3 | 2.3 | 8.9–17.8 | -0.2 | 0.6 | 61.2
25–44
Non-Hispanic:
Black | 761 | 27.0 | 1.3 | 23.8–30.3 | 25.9 | 0.8 | 24.5–27.4 | -0.8 | 0.6 | 76.4
White | 828 | 20.2 | 1.7 | 17.0–23.8 | 20.8 | 0.7 | 19.4–22.2 | 0.3 | 0.4 | 139.5
Other or multiple race | 571 | 14.4 | 2.1 | 10.6–19.0 | 16.7 | 0.9 | 15.0–18.5 | 1.1 | 0.4 | 132.8
Mexican American | 398 | 21.4 | 2.1 | 17.3–25.9 | 22.5 | 0.8 | 20.8–24.1 | 0.5 | 0.4 | 157.1
Other Hispanic | 289 | 18.8 | 2.8 | 13.5–25.1 | 20.4 | 1.0 | 18.4–22.4 | 0.6 | 0.4 | 174.7
45–64
Non-Hispanic:
Black | 962 | 26.7 | 1.7 | 23.3–30.2 | 27.5 | 1.4 | 24.8–30.2 | 0.5 | 0.8 | 25.2
White | 977 | 22.4 | 2.3 | 18.0–27.3 | 23.2 | 1.6 | 20.0–26.3 | 0.3 | 0.7 | 44.3
Other or multiple race | 614 | 13.6 | 2.8 | 8.5–20.3 | 16.8 | 1.8 | 13.2–20.3 | 1.1 | 0.6 | 55.1
Mexican American | 391 | 23.8 | 1.9 | 19.7–28.4 | 24.1 | 1.5 | 21.2–26.9 | 0.1 | 0.8 | 32.2
Other Hispanic | 345 | 19.6 | 2.8 | 14.4–25.7 | 21.2 | 1.8 | 17.7–24.7 | 0.6 | 0.7 | 53.8
65 and older
Non-Hispanic:
Black | 564 | 24.2 | 2.2 | 20.0–28.7 | 24.3 | 1.5 | 21.3–27.3 | 0.1 | 0.7 | 40.4
White | 1,216 | 19.5 | 1.2 | 17.2–21.9 | 19.8 | 1.0 | 17.8–21.8 | 0.3 | 0.9 | 15.4
Other or multiple race | 265 | 11.1 | 2.5 | 6.7–17.0 | 13.4 | 1.7 | 10.0–16.8 | 0.9 | 0.7 | 43.3
Mexican American | 159 | 19.8 | 4.2 | 12.1–29.5 | 21.2 | 2.0 | 17.2–25.2 | 0.3 | 0.5 | 106.2
Other Hispanic | 207 | 22.7 | 3.8 | 15.7–31.1 | 22.3 | 2.0 | 18.4–26.2 | -0.1 | 0.5 | 88.5
18–24 | Cubic
Non-Hispanic:
Black | 268 | 10.9 | 2.7 | 6.1–17.5 | 11.3 | 2.3 | 6.8–15.8 | 0.2 | 0.8 | 18.9
White | 349 | 7.3 | 1.8 | 4.2–11.7 | 7.5 | 1.6 | 4.4–10.6 | 0.1 | 0.9 | 12.9
Other or multiple race | 196 | 7.7 | 1.8 | 4.4–12.3 | 7.2 | 1.6 | 4.1–10.4 | -0.2 | 0.9 | 13.0
Mexican American | 183 | 5.2 | 1.3 | 2.5–9.5 | 5.6 | 1.2 | 3.2–8.1 | 0.3 | 0.9 | 8.1
Other Hispanic | 150 | 12.4 | 3.4 | 6.4–20.9 | 10.0 | 2.4 | 5.2–14.8 | -0.7 | 0.7 | 40.4
25–44
Non-Hispanic:
Black | 761 | 21.6 | 1.5 | 18.7–24.7 | 20.9 | 1.3 | 18.2–23.5 | -0.5 | 0.9 | 10.5
White | 828 | 14.0 | 1.3 | 11.6–16.7 | 14.0 | 1.2 | 11.7–16.3 | 0.0 | 0.9 | 7.2
Other or multiple race | 571 | 10.2 | 1.5 | 7.5–13.5 | 9.9 | 1.3 | 7.3–12.6 | -0.2 | 0.9 | 10.7
Mexican American | 398 | 15.2 | 2.5 | 10.6–20.9 | 15.6 | 2.0 | 11.7–19.6 | 0.2 | 0.8 | 24.1
Other Hispanic | 289 | 11.2 | 1.8 | 7.8–15.4 | 11.8 | 1.6 | 8.7–14.9 | 0.3 | 0.9 | 12.4
45–64
Non-Hispanic:
Black | 962 | 19.9 | 1.4 | 17.2–22.9 | 20.2 | 1.4 | 17.5–22.8 | 0.2 | 1.0 | 5.8
White | 977 | 18.9 | 2.4 | 14.4–24.1 | 17.8 | 2.0 | 13.9–21.7 | -0.5 | 0.8 | 21.0
Other or multiple race | 614 | 9.5 | 1.8 | 6.2–13.7 | 9.8 | 1.7 | 6.6–13.1 | 0.2 | 0.9 | 9.7
Mexican American | 391 | 20.5 | 1.7 | 16.6–24.8 | 19.6 | 1.5 | 16.6–22.5 | -0.5 | 0.9 | 9.3
Other Hispanic | 345 | 14.7 | 2.0 | 10.9–19.2 | 14.7 | 1.8 | 11.2–18.2 | 0.0 | 0.9 | 14.0
65 and older
Non-Hispanic:
Black | 564 | 18.2 | 2.0 | 14.4–22.6 | 18.3 | 1.8 | 14.8–21.8 | 0.0 | 0.9 | 13.9
White | 1,216 | 14.8 | 1.4 | 12.2–17.8 | 14.7 | 1.3 | 12.2–17.3 | -0.1 | 0.9 | 8.2
Other or multiple race | 265 | 9.4 | 2.2 | 5.5–14.7 | 8.9 | 1.9 | 5.2–12.6 | -0.2 | 0.9 | 16.0
Mexican American | 159 | 15.7 | 3.3 | 9.7–23.3 | 16.1 | 2.5 | 11.1–21.1 | 0.1 | 0.8 | 29.8
Other Hispanic | 207 | 19.5 | 4.1 | 12.1–28.9 | 16.6 | 2.8 | 11.2–22.0 | -0.7 | 0.7 | 46.9

0.0 Quantity more than zero but less than 0.05.

1 Korn–Graubard 95% confidence interval.

2 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

3 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

4 The standardized difference between the enhanced modified Kalman filter (eMKF) (model-based) and direct estimates is calculated as: (eMKF estimate minus direct estimate) divided by direct SE.

5 Relative RMSE (RRMSE) is calculated as the ratio: eMKF RMSE divided by direct RMSE.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–March 2020.

Table H Comparison of direct estimates to enhanced modified Kalman filter-based estimates for simulated trends in the prevalence of obesity, by age group and race and ethnicity where trends vary by group: National Health and Nutrition Examination Survey, 1999–March 2020

Age group and race and ethnicity | Sample size | Direct estimate | Standard error | 95% confidence interval^1^ | Model-based estimate | RMSE^2^ | 95% confidence interval^3^ | Standardized difference^4^ | RRMSE^5^ | Percent increase in equivalent sample size
18–24 | Linear
Non-Hispanic:
Black | 268 | 37.8 | 3.5 | 30.9–45.2 | 39.2 | 3.3 | 32.8–45.6 | 0.4 | 0.9 | 8.7
White | 349 | 51.7 | 3.8 | 44.0–59.4 | 48.6 | 3.3 | 42.2–55.0 | -0.8 | 0.9 | 16.8
Other or multiple race | 196 | 25.8 | 4.8 | 16.7–36.6 | 30.5 | 4.2 | 22.3–38.7 | 1.0 | 0.9 | 14.9
Mexican American | 183 | 48.3 | 4.6 | 38.9–57.8 | 46.3 | 3.7 | 39.0–53.5 | -0.4 | 0.8 | 25.6
Other Hispanic | 150 | 47.3 | 4.8 | 37.7–57.1 | 43.9 | 3.8 | 36.4–51.5 | -0.7 | 0.8 | 24.1
25–44
Non-Hispanic:
Black | 761 | 51.8 | 2.0 | 47.9–55.8 | 52.1 | 1.8 | 48.5–55.6 | 0.1 | 0.9 | 8.0
White | 828 | 56.0 | 1.7 | 52.6–59.5 | 54.8 | 1.7 | 51.6–58.0 | -0.7 | 1.0 | 4.9
Other or multiple race | 571 | 40.4 | 2.3 | 35.9–45.0 | 39.8 | 2.1 | 35.8–43.8 | -0.3 | 0.9 | 10.5
Mexican American | 398 | 55.0 | 4.0 | 46.7–63.0 | 53.1 | 3.1 | 47.0–59.2 | -0.5 | 0.8 | 29.7
Other Hispanic | 289 | 52.3 | 3.6 | 44.9–59.5 | 51.4 | 2.9 | 45.7–57.1 | -0.2 | 0.8 | 23.5
45–64
Non-Hispanic:
Black | 962 | 50.6 | 2.3 | 46.0–55.3 | 51.5 | 2.0 | 47.6–55.4 | 0.4 | 0.9 | 16.9
White | 977 | 54.3 | 1.7 | 50.9–57.7 | 53.6 | 1.6 | 50.5–56.7 | -0.4 | 0.9 | 6.9
Other or multiple race | 614 | 37.2 | 2.7 | 31.8–42.8 | 36.5 | 2.3 | 32.0–41.0 | -0.3 | 0.8 | 18.5
Mexican American | 391 | 56.3 | 3.0 | 50.3–62.2 | 55.4 | 2.4 | 50.8–60.1 | -0.3 | 0.8 | 24.7
Other Hispanic | 345 | 53.7 | 3.1 | 47.5–59.8 | 52.2 | 2.4 | 47.4–56.9 | -0.5 | 0.8 | 27.0
65 and older
Non-Hispanic:
Black | 564 | 40.4 | 2.4 | 35.6–45.3 | 42.7 | 2.2 | 38.4–47.1 | 1.0 | 0.9 | 9.1
White | 1,216 | 50.6 | 2.5 | 45.7–55.6 | 49.5 | 2.2 | 45.1–53.9 | -0.4 | 0.9 | 10.5
Other or multiple race | 265 | 30.0 | 5.0 | 20.5–41.0 | 32.1 | 3.6 | 25.0–39.3 | 0.4 | 0.7 | 38.0
Mexican American | 159 | 49.0 | 5.3 | 38.2–59.9 | 50.0 | 3.6 | 43.0–57.1 | 0.2 | 0.7 | 48.1
Other Hispanic | 207 | 49.0 | 5.2 | 38.5–59.6 | 45.9 | 3.6 | 38.9–53.0 | -0.6 | 0.7 | 44.4
18–24 | Quadratic
Non-Hispanic:
Black | 268 | 31.4 | 2.6 | 25.9–37.3 | 32.2 | 2.4 | 27.5–36.8 | 0.3 | 0.9 | 9.4
White | 349 | 44.9 | 4.3 | 36.3–53.8 | 42.5 | 3.5 | 35.5–49.4 | -0.6 | 0.8 | 22.1
Other or multiple race | 196 | 20.7 | 4.1 | 13.2–30.1 | 23.8 | 3.4 | 17.0–30.5 | 0.7 | 0.8 | 19.0
Mexican American | 183 | 39.8 | 4.4 | 31.1–49.0 | 39.4 | 3.5 | 32.5–46.3 | -0.1 | 0.8 | 24.8
Other Hispanic | 150 | 39.1 | 4.8 | 29.6–49.2 | 37.8 | 3.8 | 30.3–45.3 | -0.3 | 0.8 | 26.2
25–44
Non-Hispanic:
Black | 761 | 44.2 | 1.8 | 40.6–47.9 | 44.7 | 1.7 | 41.3–48.1 | 0.2 | 1.0 | 4.5
White | 828 | 48.8 | 1.8 | 45.2–52.4 | 47.9 | 1.7 | 44.5–51.3 | -0.5 | 1.0 | 5.0
Other or multiple race | 571 | 33.1 | 2.2 | 28.8–37.7 | 33.2 | 2.0 | 29.2–37.2 | 0.0 | 0.9 | 7.9
Mexican American | 398 | 47.6 | 3.8 | 39.9–55.4 | 47.0 | 3.2 | 40.9–53.2 | -0.1 | 0.8 | 21.1
Other Hispanic | 289 | 46.3 | 3.0 | 40.4–52.3 | 46.3 | 2.6 | 41.2–51.5 | 0.0 | 0.9 | 13.0
45–64
Non-Hispanic:
Black | 962 | 44.3 | 2.3 | 39.7–49.0 | 45.3 | 2.1 | 41.2–49.3 | 0.4 | 0.9 | 12.4
White | 977 | 46.7 | 2.1 | 42.5–50.9 | 46.8 | 1.9 | 43.0–50.5 | 0.0 | 0.9 | 9.5
Other or multiple race | 614 | 26.6 | 3.0 | 20.9–32.9 | 27.9 | 2.5 | 22.9–32.9 | 0.4 | 0.9 | 16.9
Mexican American | 391 | 50.4 | 3.0 | 44.5–56.4 | 50.6 | 2.5 | 45.7–55.4 | 0.0 | 0.8 | 19.6
Other Hispanic | 345 | 45.4 | 2.3 | 40.0–50.8 | 45.4 | 2.0 | 41.4–49.4 | 0.0 | 0.9 | 11.9
65 and older
Non-Hispanic:
Black | 564 | 36.4 | 2.5 | 31.6–41.5 | 37.8 | 2.3 | 33.3–42.3 | 0.6 | 0.9 | 8.3
White | 1,216 | 44.6 | 2.7 | 39.3–50.0 | 44.4 | 2.4 | 39.6–49.2 | -0.1 | 0.9 | 9.7
Other or multiple race | 265 | 23.6 | 3.7 | 16.7–31.8 | 24.8 | 3.1 | 18.6–31.0 | 0.3 | 0.9 | 16.9
Mexican American | 159 | 41.0 | 4.8 | 31.5–51.0 | 43.2 | 3.7 | 36.0–50.5 | 0.5 | 0.8 | 29.8
Other Hispanic | 207 | 42.8 | 3.8 | 35.3–50.6 | 41.8 | 3.2 | 35.6–48.1 | -0.3 | 0.8 | 18.9
18–24 | Cubic
Non-Hispanic:
Black | 268 | 25.0 | 2.3 | 19.9–30.6 | 26.4 | 2.2 | 22.0–30.7 | 0.6 | 1.0 | 3.7
White | 349 | 38.7 | 4.4 | 30.0–48.0 | 37.0 | 3.8 | 29.6–44.4 | -0.4 | 0.9 | 17.7
Other or multiple race | 196 | 13.6 | 2.7 | 8.7–19.7 | 16.1 | 2.6 | 11.0–21.2 | 1.0 | 1.0 | 1.6
Mexican American | 183 | 31.6 | 4.3 | 23.2–40.9 | 32.9 | 3.8 | 25.5–40.2 | 0.3 | 0.9 | 15.5
Other Hispanic | 150 | 31.6 | 5.1 | 21.9–42.6 | 32.7 | 4.1 | 24.6–40.7 | 0.2 | 0.8 | 23.2
25–44
Non-Hispanic:
Black | 761 | 34.6 | 1.6 | 31.2–38.1 | 35.5 | 1.6 | 32.4–38.6 | 0.6 | 1.0 | 1.6
White | 828 | 39.7 | 1.6 | 36.4–43.1 | 39.7 | 1.5 | 36.7–42.8 | 0.0 | 1.0 | 3.5
Other or multiple race | 571 | 24.4 | 2.3 | 20.0–29.3 | 25.8 | 2.2 | 21.5–30.1 | 0.6 | 1.0 | 5.5
Mexican American | 398 | 39.3 | 3.2 | 33.1–45.9 | 40.7 | 2.8 | 35.1–46.2 | 0.4 | 0.9 | 12.2
Other Hispanic | 289 | 36.1 | 2.9 | 30.3–42.1 | 37.9 | 2.7 | 32.7–43.2 | 0.6 | 0.9 | 8.9
45–64
Non-Hispanic:
Black | 962 | 35.0 | 1.8 | 31.4–38.7 | 36.2 | 1.8 | 32.7–39.7 | 0.6 | 1.0 | 2.7
White | 977 | 38.4 | 2.0 | 34.6–42.4 | 39.2 | 1.9 | 35.6–42.9 | 0.4 | 1.0 | 4.6
Other or multiple race | 614 | 21.8 | 2.7 | 16.6–27.7 | 23.4 | 2.5 | 18.5–28.4 | 0.6 | 0.9 | 7.5
Mexican American | 391 | 40.9 | 3.3 | 34.3–47.6 | 43.1 | 2.9 | 37.4–48.8 | 0.7 | 0.9 | 13.4
Other Hispanic | 345 | 38.7 | 3.1 | 32.7–45.0 | 39.8 | 2.8 | 34.4–45.2 | 0.3 | 0.9 | 11.1
65 and older
Non-Hispanic:
Black | 564 | 27.3 | 2.2 | 23.1–31.8 | 28.6 | 2.1 | 24.5–32.7 | 0.6 | 1.0 | 4.0
White | 1,216 | 36.9 | 2.6 | 31.7–42.3 | 37.3 | 2.5 | 32.4–42.3 | 0.2 | 1.0 | 5.4
Other or multiple race | 265 | 16.2 | 2.6 | 11.4–22.1 | 17.3 | 2.5 | 12.4–22.1 | 0.4 | 0.9 | 6.3
Mexican American | 159 | 30.9 | 5.7 | 20.1–43.6 | 35.9 | 4.5 | 27.1–44.7 | 0.9 | 0.8 | 27.5
Other Hispanic | 207 | 35.6 | 3.5 | 28.7–43.0 | 35.6 | 3.2 | 29.4–41.9 | 0.0 | 0.9 | 10.0

0.0 Quantity more than zero but less than 0.05.

1 Korn–Graubard 95% confidence interval.

2 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

3 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

4 The standardized difference between the enhanced modified Kalman filter (eMKF) (model-based) and direct estimates is calculated as: (eMKF estimate minus direct estimate) divided by direct SE.

5 Relative RMSE (RRMSE) is calculated as the ratio: eMKF RMSE divided by direct RMSE.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–March 2020.

Table J Comparison of direct estimates to enhanced modified Kalman filter-based estimates for simulated trends in prevalence of severe obesity, by age group and race and ethnicity where trends vary by group: National Health and Nutrition Examination Survey, 1999–March 2020

Age group and race and ethnicity | Sample size | Direct estimate | Standard error | 95% confidence interval^1^ | Model-based estimate | RMSE^2^ | 95% confidence interval^3^ | Standardized difference^4^ | RRMSE^5^ | Percent increase in equivalent sample size
18–24 | Linear
Non-Hispanic:
Black | 268 | 12.5 | 2.0 | 8.8–17.1 | 12.2 | 1.7 | 8.9–15.6 | -0.1 | 0.9 | 16.1
White | 349 | 21.4 | 4.3 | 13.5–31.2 | 14.3 | 2.7 | 8.9–19.6 | -1.7 | 0.6 | 57.3
Other or multiple race | 196 | 5.9 | 1.6 | 3.0–10.2 | 6.2 | 1.4 | 3.3–9.0 | 0.2 | 0.9 | 8.7
Mexican American | 183 | 18.4 | 4.8 | 9.8–30.1 | 13.4 | 2.7 | 8.1–18.8 | -1.0 | 0.6 | 76.9
Other Hispanic | 150 | 11.8 | 2.6 | 7.1–18.1 | 10.4 | 2.1 | 6.4–14.5 | -0.5 | 0.8 | 25.9
25–44
Non-Hispanic:
Black | 761 | 18.3 | 1.9 | 14.7–22.5 | 18.7 | 1.6 | 15.5–21.9 | 0.2 | 0.8 | 19.9
White | 828 | 20.7 | 1.6 | 17.7–23.9 | 18.8 | 1.4 | 16.1–21.6 | -1.2 | 0.9 | 11.1
Other or multiple race | 571 | 9.6 | 1.4 | 7.0–12.7 | 9.3 | 1.2 | 6.9–11.8 | -0.2 | 0.9 | 13.0
Mexican American | 398 | 21.9 | 2.3 | 17.5–26.9 | 20.1 | 1.8 | 16.5–23.6 | -0.8 | 0.8 | 28.0
Other Hispanic | 289 | 19.3 | 2.2 | 14.9–24.3 | 18.9 | 1.7 | 15.5–22.3 | -0.2 | 0.8 | 27.1
45–64
Non-Hispanic:
Black | 962 | 18.2 | 1.6 | 15.1–21.6 | 18.6 | 1.5 | 15.7–21.5 | 0.2 | 0.9 | 9.8
White | 977 | 22.5 | 1.3 | 19.9–25.2 | 21.7 | 1.3 | 19.2–24.1 | -0.6 | 1.0 | 5.0
Other or multiple race | 614 | 8.8 | 2.0 | 5.2–13.7 | 8.3 | 1.7 | 4.9–11.8 | -0.2 | 0.9 | 16.7
Mexican American | 391 | 22.4 | 2.3 | 18.0–27.3 | 20.9 | 1.9 | 17.1–24.8 | -0.6 | 0.9 | 17.8
Other Hispanic | 345 | 21.8 | 2.8 | 16.5–27.8 | 18.5 | 2.2 | 14.1–22.8 | -1.2 | 0.8 | 24.3
65 and older
Non-Hispanic:
Black | 564 | 13.0 | 1.8 | 9.8–16.9 | 13.8 | 1.4 | 11.0–16.5 | 0.4 | 0.8 | 24.4
White | 1,216 | 17.5 | 1.7 | 14.3–21.0 | 15.9 | 1.5 | 12.9–18.8 | -1.0 | 0.9 | 9.7
Other or multiple race | 265 | 7.3 | 1.7 | 4.3–11.4 | 7.4 | 1.4 | 4.7–10.1 | 0.1 | 0.8 | 21.6
Mexican American | 159 | 13.0 | 3.6 | 6.7–22.0 | 14.2 | 2.0 | 10.2–18.2 | 0.3 | 0.6 | 78.7
Other Hispanic | 207 | 18.6 | 3.3 | 12.5–26.2 | 12.6 | 2.2 | 8.3–16.9 | -1.8 | 0.7 | 52.9
18–24 | Quadratic
Non-Hispanic:
Black | 268 | 10.5 | 2.0 | 7.0–15.0 | 10.5 | 1.7 | 7.2–13.8 | 0.0 | 0.9 | 15.5
White | 349 | 15.2 | 2.8 | 10.1–21.5 | 12.9 | 2.0 | 8.9–16.9 | -0.8 | 0.7 | 35.2
Other or multiple race | 196 | 4.3 | 1.1 | 1.9–8.2 | 4.7 | 1.1 | 2.5–6.8 | 0.3 | 1.0 | 2.6
Mexican American | 183 | 12.4 | 3.3 | 6.5–20.6 | 11.6 | 2.3 | 7.1–16.0 | -0.2 | 0.7 | 47.0
Other Hispanic | 150 | 10.1 | 3.1 | 4.8–18.0 | 9.2 | 2.2 | 4.8–13.5 | -0.3 | 0.7 | 39.6
25–44
Non-Hispanic:
Black | 761 | 14.4 | 1.3 | 11.8–17.2 | 15.0 | 1.2 | 12.6–17.5 | 0.5 | 0.9 | 8.9
White | 828 | 16.6 | 1.4 | 14.0–19.4 | 15.6 | 1.2 | 13.1–18.0 | -0.7 | 0.9 | 9.6
Other or multiple race | 571 | 6.0 | 0.9 | 4.2–8.2 | 6.2 | 0.9 | 4.4–7.9 | 0.2 | 1.0 | 5.4
Mexican American | 398 | 19.3 | 2.0 | 15.4–23.6 | 18.0 | 1.7 | 14.7–21.3 | -0.6 | 0.8 | 20.6
Other Hispanic | 289 | 15.3 | 2.3 | 11.0–20.5 | 15.7 | 1.9 | 12.0–19.4 | 0.2 | 0.8 | 24.1
45–64
Non-Hispanic:
Black | 962 | 14.1 | 1.4 | 11.5–17.1 | 14.7 | 1.3 | 12.2–17.2 | 0.4 | 0.9 | 8.9
White | 977 | 19.3 | 1.5 | 16.5–22.4 | 18.4 | 1.4 | 15.7–21.1 | -0.6 | 0.9 | 9.1
Other or multiple race | 614 | 5.1 | 1.1 | 3.2–7.8 | 5.2 | 1.0 | 3.2–7.3 | 0.1 | 0.9 | 7.1
Mexican American | 391 | 18.0 | 2.1 | 14.1–22.4 | 17.3 | 1.7 | 13.9–20.7 | -0.3 | 0.8 | 18.7
Other Hispanic | 345 | 17.2 | 2.4 | 12.8–22.5 | 15.2 | 1.9 | 11.5–18.9 | -0.9 | 0.8 | 26.7
65 and older
Non-Hispanic:
Black | 564 | 9.6 | 1.5 | 7.0–12.9 | 10.4 | 1.3 | 7.8–12.9 | 0.5 | 0.9 | 12.8
White | 1,216 | 13.9 | 1.1 | 11.8–16.2 | 13.5 | 1.0 | 11.5–15.5 | -0.3 | 0.9 | 7.4
Other or multiple race | 265 | 4.7 | 1.5 | 2.2–8.5 | 5.1 | 1.3 | 2.6–7.7 | 0.3 | 0.9 | 12.4
Mexican American | 159 | 9.3 | 2.5 | 5.0–15.5 | 10.8 | 1.9 | 7.2–14.5 | 0.6 | 0.8 | 34.1
Other Hispanic | 207 | 11.6 | 2.8 | 6.7–18.3 | 9.4 | 2.0 | 5.4–13.3 | -0.8 | 0.7 | 38.9
18–24 | Cubic
Non-Hispanic:
Black | 268 | 9.2 | 2.0 | 5.7–14.1 | 9.7 | 1.5 | 6.8–12.6 | 0.2 | 0.7 | 35.7
White | 349 | 11.6 | 2.8 | 6.7–18.5 | 9.6 | 1.9 | 5.9–13.2 | -0.7 | 0.7 | 51.6
Other or multiple race | 196 | 2.0 | 1.2 | 0.4–6.0 | 3.0 | 1.1 | 0.8–5.1 | 0.8 | 0.9 | 9.6
Mexican American | 183 | 7.0 | 2.2 | 3.3–12.9 | 8.1 | 1.6 | 4.9–11.3 | 0.5 | 0.7 | 38.2
Other Hispanic | 150 | 7.6 | 2.4 | 3.6–13.9 | 7.3 | 1.7 | 3.9–10.7 | -0.1 | 0.7 | 40.5
25–44
Non-Hispanic:
Black | 761 | 10.1 | 1.0 | 8.1–12.5 | 11.0 | 1.0 | 9.1–12.9 | 1.0 | 1.0 | -0.1
White | 828 | 11.8 | 1.3 | 9.5–14.5 | 11.8 | 1.2 | 9.6–14.1 | 0.0 | 0.9 | 8.7
Other or multiple race | 571 | 4.4 | 0.8 | 2.9–6.5 | 4.7 | 0.8 | 3.1–6.3 | 0.3 | 1.0 | 3.8
Mexican American | 398 | 15.4 | 1.7 | 12.0–19.4 | 15.3 | 1.5 | 12.4–18.1 | -0.1 | 0.9 | 15.4
Other Hispanic | 289 | 12.3 | 2.0 | 8.7–16.9 | 14.0 | 1.7 | 10.6–17.4 | 0.8 | 0.9 | 16.4
45–64
Non-Hispanic:
Black | 962 | 10.4 | 1.0 | 8.5–12.5 | 10.8 | 1.0 | 9.0–12.7 | 0.5 | 1.0 | 1.6
White | 977 | 13.7 | 1.4 | 11.0–16.7 | 13.9 | 1.3 | 11.3–16.4 | 0.1 | 0.9 | 6.2
Other or multiple race | 614 | 3.1 | 0.8 | 1.8–5.0 | 3.2 | 0.8 | 1.7–4.7 | 0.2 | 1.0 | 1.8
Mexican American | 391 | 12.5 | 1.2 | 9.4–16.2 | 12.9 | 1.2 | 10.6–15.2 | 0.3 | 1.0 | 4.6
Other Hispanic | 345 | 13.1 | 2.2 | 9.1–18.1 | 13.1 | 1.9 | 9.4–16.8 | 0.0 | 0.9 | 15.4
65 and older
Non-Hispanic:
Black | 564 | 6.5 | 1.3 | 4.3–9.5 | 7.1 | 1.2 | 4.7–9.5 | 0.4 | 1.0 | 5.4
White | 1,216 | 10.1 | 0.8 | 8.4–11.9 | 10.1 | 0.8 | 8.4–11.7 | 0.0 | 1.0 | 1.0
Other or multiple race | 265 | 2.4 | 1.1 | 0.8–5.5 | 2.6 | 1.0 | 0.6–4.6 | 0.2 | 1.0 | 3.8
Mexican American | 159 | 6.9 | 2.4 | 3.0–13.2 | 8.4 | 2.0 | 4.4–12.3 | 0.6 | 0.9 | 16.9
Other Hispanic | 207 | 9.8 | 2.4 | 5.6–15.6 | 8.8 | 2.2 | 4.6–13.0 | -0.4 | 0.9 | 9.9

0.0 Quantity more than zero but less than 0.05.

1 Korn–Graubard 95% confidence interval.

2 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

3 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

4 The standardized difference between the enhanced modified Kalman filter (eMKF) (model-based) and direct estimates is calculated as: (eMKF estimate minus direct estimate) divided by direct SE.

5 Relative RMSE (RRMSE) is calculated as the ratio: eMKF RMSE divided by direct RMSE.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–March 2020.

Figure 6 Direct and model-based prevalence of obesity and 95% confidence intervals for adults age 65 and older, by race and ethnicity and year using simulated data under three trend shapes where groups had a common underlying trend: National Health and Nutrition Examination Survey, 1999–March 2020

NOTES: CI is confidence interval. Linear, quadratic, and cubic trends are simulated. Obesity is defined as a body mass index greater than or equal to 30 kg/m^2^. All but one of the time points on the x-axis represent standard 2-year survey data cycles—for example, 2000 represents the 1999–2000 data cycle. The exception is the last data cycle, where 2019 includes data from 2017 through March 2020.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–March 2020.

Figure 6 is a series of bar plots showing direct and model-based estimates of obesity for age 65 and older, by race and ethnicity and year using simulated data in linear, quadratic, and cubic trend forms where groups had a common trend, from National Health and Nutrition Examination Survey, 1999 through March 2020.

Figure 7 Direct and model-based prevalence of severe obesity and 95% confidence intervals for adults age 65 and older, by race and ethnicity and year using simulated data under three trend shapes where groups had a common underlying trend: National Health and Nutrition Examination Survey, 1999–March 2020

NOTES: CI is confidence interval. Linear, quadratic, and cubic trends are simulated. Severe obesity is defined as a body mass index greater than or equal to 40 kg/m^2^. All but one of the time points on the x-axis represent standard 2-year survey data cycles—for example, 2000 represents the 1999–2000 data cycle. The exception is the last data cycle, where 2019 includes data from 2017 through March 2020.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–March 2020.

Figure 7 is a series of bar plots showing direct and model-based estimates of severe obesity for age 65 and older, by race and ethnicity and year using simulated data in linear, quadratic, and cubic trend forms where groups had a common trend, from National Health and Nutrition Examination Survey, 1999 through March 2020.

Figure 8 Direct and model-based prevalence of obesity and 95% confidence intervals for adults age 65 and older, by race and ethnicity and year using simulated data under three trend shapes where groups had a unique underlying trend: National Health and Nutrition Examination Survey, 1999–March 2020

NOTES: CI is confidence interval. Linear, quadratic, and cubic trends are simulated. Obesity is defined as a body mass index greater than or equal to 30 kg/m^2^. All but one of the time points on the x-axis represent standard 2-year survey data cycles—for example, 2000 represents the 1999–2000 data cycle. The exception is the last data cycle, where 2019 includes data from 2017 through March 2020.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–March 2020.

Figure 8 is a series of bar plots showing direct and model-based estimates of obesity for age 65 and older, by race and ethnicity and year using simulated data in linear, quadratic, and cubic trend forms where groups had a unique trend, from National Health and Nutrition Examination Survey, 1999 through March 2020.

Figure 9 Direct and model-based prevalence of severe obesity and 95% confidence intervals for adults age 65 and older, by race and ethnicity and year using simulated data under three trend shapes where groups had unique underlying trends: National Health and Nutrition Examination Survey, 1999–March 2020

NOTES: CI is confidence interval. Linear, quadratic, and cubic trends are simulated. Severe obesity is defined as a body mass index greater than or equal to 40 kg/m^2^. All but one of the time points on the x-axis represent standard 2-year survey data cycles—for example, 2000 represents the 1999–2000 data cycle. The exception is the last data cycle, where 2019 includes data from 2017 through March 2020.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–March 2020.

Figure 9 is a series of bar plots showing direct and model-based estimates of severe obesity for age 65 and older, by race and ethnicity and year using simulated data in linear, quadratic, and cubic trend forms where groups had a unique trend, from National Health and Nutrition Examination Survey, 1999 through March 2020.

### Applied analysis of 1999–2018 NHIS to compare original MKF macro results with eMKF

Using annual NHIS data on 10 outcomes and 11 racial and ethnic groups, results from the original MKF macro (fully Bayesian linear trends with fixed variances) were compared with two eMKF procedures: fully Bayesian linear trends with random variances, and BMA up to cubic trends with random variances. The three sets of model-based estimates were compared with the direct estimates for each outcome, along with the corresponding standardized differences, RMSEs, RRMSEs, and the percentage increase in equivalent sample sizes.

Regardless of which MKF model was used, model-based estimates improved on the direct estimates considerably, as measured by a percentage increase in equivalent sample size ranging from 8% to about 600% across all 10 outcomes and 11 population groups, including for the 10 direct 2018 estimates shown in Appendix Tables I–X that did not meet NCHS standards of reliability.

Across most racial and ethnic subgroups and health outcomes from NHIS data, the eMKF BMA up to cubic trends with random variances offered the largest percentage increase in equivalent sample size across the three different model-based estimates (Appendix Tables I–X). A total of 110 estimates were made across 10 outcomes and 11 racial and ethnic groups, and of those, the eMKF BMA model had the largest percentage increase in equivalent sample size in 74 cases (67%). Similarly, the eMKF BMA model had the lowest RMSE in 74 cases (67%) and the smallest SEs in 80 cases (73%). In a few outcomes, the eMKF BMA was not the most accurate or efficient model across most racial and ethnic groups: heart disease, cancer, and kidney disease. These were among the less prevalent outcomes (generally less than 15%); however, other outcomes were more or equivalently rare (stroke, less than 5%), where the eMKF BMA model did outperform the other models. Consequently, the outcome prevalence does not appear to be what drove the underperformance of the eMKF BMA model relative to the linear model options.

For heart disease (Appendix Table IV), the three models performed similarly, and differences in RMSE and percentage increase in equivalent sample size were small in magnitude. For cancer and kidney disease (Appendix Tables V and VII), the linear models outperformed the eMKF BMA option across most racial and ethnic groups, with somewhat larger differences in RMSE and percentage increase in equivalent sample size.