# Methods

## Data

To evaluate the performance of the eMKF procedure, simulated data sets were constructed based on two NCHS data systems, NHIS and the National Health and Nutrition Examination Survey (NHANES). Applied analyses of actual NHIS data were also conducted to assess the performance of the eMKF procedure in generating model-based estimates for small subgroups of interest across a range of outcomes, similar to methods used in earlier evaluations of the original MKF macro (9).

### NHIS

Data from the 2019–2021 NHIS were used to construct simulated data sets representing samples of different sizes (and corresponding ranges of estimate uncertainty) based on the year and quarter of interview. Additionally, annual data from the 1999–2018 NHIS were used to evaluate the performance of the eMKF procedure in relation to the previous MKF procedure, based on applied analyses of several health outcomes included in an earlier report representing a range of sample sizes and outcome prevalences (9).

NHIS is a nationally representative household survey of the U.S. civilian noninstitutionalized population, capturing data on health status, healthcare, health behaviors, and other factors. Due to the impact of the COVID-19 pandemic, data collection for NHIS was predominantly done by telephone in 2020 and 2021, in contrast to in-person interviews in preceding years. Additionally, NHIS underwent a sample redesign in 2016 and a questionnaire redesign in 2019 (13). As a result, analyses examining the most recent trends in outcomes using NHIS data are typically limited to 2019 and later.

#### Simulated NHIS data

To create simulated data representing a range of sample sizes, NHIS data from 2019–2021 were limited to sample adults, and the demographic variables used included age group (18–49, 50–64, and 65 and older) and race and ethnicity—American Indian or Alaska Native non-Hispanic (subsequently, American Indian or Alaska Native), Asian non-Hispanic (subsequently, Asian), Black non-Hispanic (subsequently, Black), White non-Hispanic (subsequently, White), other or multiple race non-Hispanic (subsequently, other or multiple race), and Hispanic or Latino. For the simulated data sets, the three smallest racial and ethnic groups were combined into one group to establish sufficiently reliable direct estimates for comparison in the various simulated data sets. This resulted in four racial and ethnic groups: Black, White, other or multiple race, and Hispanic. Simulations were based on two outcome variables, diagnosed diabetes and history of smoking. Diagnosed diabetes was assessed based on the survey question, “Has a doctor ever told you that you have diabetes?” (not including gestational diabetes or prediabetes). History of smoking was assessed based on the question, “Have you smoked at least 100 cigarettes in your entire life?”

#### Applied analysis of 1999–2018 NHIS data

For the applied analysis of 1999–2018 NHIS data to compare the earlier MKF procedures to the eMKF procedures, annual NHIS data for adults from 1999 to 2018 were used (14). Ten outcomes were examined that were analyzed in a previous report, representing a range of higher and lower prevalence outcomes with different temporal trends (9). These outcomes included: 1) the proportion of adults with any functional limitations, 2) the proportion of adults ever diagnosed with hypertension, 3) the proportion of adults ever diagnosed with asthma, 4) the proportion of adults ever diagnosed with heart disease, 5) the proportion of adults with a history of cancer, 6) the proportion of adults who are current smokers, 7) the proportion of adults diagnosed with kidney disease in the past 12 months, 8) the proportion of adults with a history of stroke, 9) mean body mass index (BMI) among adults, and 10) mean number of bed days due to illness or injury among adults.

Any functional limitations were defined as having any difficulty doing one or more of the following activities by oneself and without any special equipment: going out to shopping, movies, sporting events, or similar activities; participating in social activities, such as visiting friends, attending clubs and meetings, and going to parties; doing things to relax at home or for leisure (reading, watching TV, sewing, or listening to music); walking one-quarter of a mile (or three city blocks); climbing 10 steps without resting; standing for 2 hours; sitting for 2 hours; stooping, bending, or kneeling; reaching over one’s head; using one’s fingers to grasp or handle small objects; lifting or carrying a 10-pound object (such as a full bag of groceries); and pushing or pulling a large object (such as a living room chair).

Hypertension was defined as having been told by a doctor or other health professional that one was hypertensive (or with high blood pressure) on at least two different visits. Lifetime asthma prevalence was defined as ever having been told by a doctor or other health professional that one had asthma. Heart disease was defined as ever having been told by a doctor or other health professional that one had coronary heart disease, angina, heart attack, or any other heart condition or disease. Cancer was defined as ever having been told by a doctor or other health professional that one had cancer or malignancy of any kind.

Current smoking was defined as having smoked at least 100 cigarettes in one’s lifetime and currently still smoking. Kidney disease was defined as having been told in the last 12 months by a doctor or other health professional that one had weak or failing kidneys (excluding kidney stones, bladder infections, or incontinence). Stroke was defined as having been told by a doctor or other health professional that one had had a stroke.

The mean BMI was calculated from information that respondents supplied in response to survey questions regarding height and weight and defined as BMI = weight (kilograms) / [height (meters)]^2^. The mean number of bed days per person was calculated from information that respondents supplied in response to the question, “During the past 12 months, about how many days did illness or injury keep you in the bed more than half of the day (include days while an overnight patient in a hospital)?”

Each of these 10 outcomes was estimated by selected race and Hispanic ethnicity categories, consistent with those used in the earlier study (9), to include the following single-race non-Hispanic populations: American Indian or Alaska Native, Asian of Chinese origin, Asian of Filipino origin, Asian of Indian origin, Black, and White; as well as the following Hispanic or Latino subgroups: Hispanic of Puerto Rican origin, Hispanic of Mexican or Mexican American origin, Hispanic of Cuban origin, and Hispanic of all other national origins, including multiple origins. The category “All other population subgroups” included the Pacific Islander non-Hispanic only population, other Asian non-Hispanic only subgroups, and multiracial populations.

### NHANES

Data from the 1999–March 2020 NHANES were used to construct simulated data sets representing different temporal trend forms (linear, quadratic, and cubic) with unequally spaced time intervals. NHANES is a nationally representative survey of the U.S. civilian noninstitutionalized population capturing both self-reported health data through in-person interviews as well as measured health status assessed through health examinations and laboratory tests. Since 1999, NHANES has been conducted as a continuous survey, released in 2-year cycles. However, the COVID-19 pandemic led to a pause in field operations in early 2020. As a result, only partial data from the 2019–2020 cycle was available. To provide nationally representative data for those years, the data collected from 2019 through March 2020 were combined with data from the preceding cycle (2017–2018, which is also separately available as a 2-year cycle). This data set is referred to as the prepandemic data file (15). The pandemic-related disruption and subsequent data file release created unequal time intervals when the prepandemic data file (2017 through March 2020) is used in combination with previous 2-year cycles of NHANES (1999–2000, 2001–2002, 2003–2004, 2005–2006, 2007–2008, 2009–2010, 2011– 2012, 2013–2014, and 2015–2016). While restricted data may have year of examination available within the data files, the public-use files only have 2-year cycles—as a result, this report defines time as the midpoint of the cycles. In addition to the prepandemic data file creating unequally spaced time periods, the last prepandemic cycle covers a 3.2-year period instead of the usual 2-year cycle.

#### Simulated NHANES data

To create simulated trend scenarios, NHANES data from 1999–March 2020 were limited to adults age 18 and older, and the demographic variables used included age group (18–24, 25–44, 45–64, and 65 and older) and race and ethnicity (Mexican American, other Hispanic, Black non-Hispanic, White non-Hispanic, and other or multiple race non-Hispanic). The main outcome for the simulated data sets was BMI, where various trends in population-level BMI were simulated (described below). Two outcomes were derived from these simulated BMI estimates: 1) the prevalence of obesity (BMI ≥ 30 kg/m^2^) and 2) the prevalence of severe obesity (BMI ≥ 40 kg/m^2^). The prevalence of each of these two outcomes was estimated by population subgroup and time period (the midpoint of each data cycle).

## Statistical Analysis

### Simulations

Several different simulated data sets were used to examine the performance of the eMKF macro under different scenarios: evaluating 1) the impact of sample size (and relatedly, estimate precision) and 2) the shape of the underlying trend over time (linear, quadratic, and cubic) and whether trends were common or distinct across subgroups. For each of these two main scenarios, outcomes with different prevalence (lower compared with higher) were included.

The performance of the eMKF macro was also assessed by several criteria to describe the accuracy and precision of the model-based estimates compared with the simulated direct estimates. Overall accuracy was assessed by the root mean squared error (RMSE) and relative RMSE (RRMSE). Precision was assessed using the width of 95% confidence intervals (95% CI). Additionally, standardized differences between the model-based and direct estimates were examined to quantify the magnitude of the differences between them. The goal of evaluating performance under these various simulated scenarios was to inform different analytic choices that data users may make and to identify situations where producing model-based estimates using the eMKF macro may not be advised (as when sample sizes are too small, or the outcome is too rare, to get accurate or precise model-based estimates).

#### Simulation scenario 1: Sample size and estimate precision

Quarterly data from the 2019–2021 NHIS were used to evaluate the performance of the eMKF macro by sample size and to potentially determine a rule of thumb regarding either sample size or precision (as in 95% CI width) where reasonable model-based estimates cannot be obtained. These data were treated as the true population, and several subsamples were drawn representing increasingly smaller sample sizes (and correspondingly larger levels of uncertainty) when stratified by population subgroup. The largest subsample size consisted of 40% of the adult NHIS sample, the medium subsample size was 20% of the adult sample, and the small subsample size was 10% of the adult sample. For each of these three subsample sizes, 1,000 replicate subsamples were simulated.

The total sample sizes averaged 765, 1,515, and 3,019 for the small, medium, and large scenarios, respectively (Table A). While these total subsample sizes may not be considered very small, the subsample sizes by age and population group varied from 12 to 746 and reflected situations commonly encountered by NCHS data analysts, where estimates for some larger subgroups may meet presentation standards but estimates for smaller subgroups would be suppressed.

Table A Unweighted sample sizes, by simulation scenario, age group, and population group: National Health Interview Survey, 2021, Quarter 4

Sample scenario andpopulation group | 18–49 | 50–64 | 65 and older
Total sample
Total | 3,289 | 1,896 | 2,354
Non-Hispanic:
Black | 350 | 225 | 210
White | 1,856 | 1,295 | 1,832
Other or multiple race | 397 | 146 | 128
Hispanic | 686 | 230 | 184
Large subsample (40%)
Total | 1,316 | 758 | 945
Non-Hispanic:
Black | 137 | 91 | 85
White | 746 | 515 | 732
Other or multiple race | 157 | 58 | 52
Hispanic | 276 | 94 | 76
Medium subsample (20%)
Total | 657 | 383 | 475
Non-Hispanic:
Black | 67 | 47 | 42
White | 378 | 258 | 370
Other or multiple race | 77 | 31 | 26
Hispanic | 135 | 47 | 37
Small subsample (10%)
Total | 331 | 194 | 240
Non-Hispanic:
Black | 33 | 21 | 22
White | 190 | 131 | 187
Other or multiple race | 40 | 17 | 12
Hispanic | 68 | 25 | 19

NOTE: Estimates reflect average unweighted sample sizes by age and subgroup across 1,000 simulated subsamples.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2021, Quarter 4.

Each of these three simulated scenarios (large, medium, or small samples) were applied to two outcomes, one more prevalent (ever smoked 100 or more cigarettes) and one less prevalent (diagnosed diabetes), for a total of six simulated scenarios. Direct estimates from the total NHIS sample were used as a gold standard to compare with subsample model-based estimates and subsample direct estimates.

#### Simulation scenario 2: Trend form

To evaluate how well the eMKF procedures capture various nonlinear trends, data from the 1999–March 2020 NHANES were used to simulate linear, quadratic, and cubic trends in the prevalence of obesity and severe obesity.

##### Linear

Linear trends in BMI as a continuous variable were simulated by first taking the mean BMI (BMI_g_) by age group, race and ethnicity, sex, and income-to-poverty ratio (excluding 8% of respondents with missing values) and then simulating a linear trend for year (β_1_), based on a normal distribution with mean 0.5 and standard deviation of 0.5. Error terms (ε) were simulated from a normal distribution with mean 0 and standard deviation of 10:

Y_sim_ = BMI_g_ + β_1_ · year + ε (1)

##### Quadratic

Similarly, quadratic trends were simulated using,

Y_sim_ = BMI_g_ + β_1_ · year + β_2_ · year^2^ + ε (2)

where β_2_ was simulated from a normal distribution with mean –0.03, standard deviation of 0.03, and year centered at 2010.

##### Cubic

Finally, cubic trends were simulated using,

Y_sim_ = BMI_g_ + β_1_ · year + β_2_ · year^2^ + β_3_ · year^3^ + ε (3)

where β_3_ was simulated from a normal distribution with mean –0.005, standard deviation of 0.005, and year centered at 2010.

In each of the above scenarios, the trends for each population subgroup were drawn from the same distribution (that is, common trends). A second set of simulated trends was generated where the trends varied by age group and race and ethnicity (that is, unique trends). In these scenarios, the linear trend component was multiplied by a factor unique to each population subgroup, such that the resulting simulated slope of the linear trends varied by group but the shape of the trend (linear, quadratic, or cubic) remained consistent across all groups.

Based on these six simulated trend data sets—linear, quadratic, and cubic, and trends common across groups or unique by group (age group and race and ethnicity)—the prevalence of obesity and severe obesity were then estimated based on a BMI ≥ 30 kg/m^2^ and a BMI ≥ 40 kg/m^2^, respectively. This provides a total of 12 simulated scenarios.

### The eMKF Bayesian model averaging implementation

For each of the 18 simulated data sets (6 sample size scenarios based on NHIS data and 12 trend scenarios based on NHANES data), the Bayesian model averaging (BMA) up to cubic trends option was used in the eMKF macro. The model-based estimates and RMSEs were obtained for each racial and ethnic group, age group, and time period (quarter or year) and used to construct Wald 95% CIs.

The SAS code (call) to run the eMKF macro can be seen in the following sample code, using 20,000 burn-in iterations (nbi) and a Markov chain Monte Carlo (MCMC) sample of 25,000 after thinning (25,000 = 50,000/2 = nmc/thin):

%mkf(data       = sim1,    group       = race,    by          = agegroup,    time        = year,    outcome     = diabetes,    se          = se_diabetes,    neff        = neff_diabetes,    Bayesmodel  = bma_cubic,    nbi         = 20000,    nmc         = 50000,    thin        = 2,    seed        = 44,    mcmcplot    = YES,    GRthreshold = 1.1,    modelprint  = YES,    out         = sm_bmac);

Four chains are used by default for Bayesian estimation in the eMKF macro, and values of the Gelman–Rubin diagnostic above 1.1 flag potential issues with model convergence. A seed was set to ensure results could be replicated across repeated analyses. Detailed diagnostic statistics and plots are requested using the mcmcplot and modelprint macro parameters. Technical guidance regarding the eMKF macro parameters and settings is available (8).

Model-based estimates were then compared with the direct estimates. Plots of the model-based and direct estimates by time period, age group, race and ethnicity, and outcome were generated, along with the corresponding 95% CIs. These plots were used to visually inspect how well the model-based estimates captured the temporal trends in the simulated data sets. Several other metrics were used to compare estimates, including:

- RMSE—Defined as the square root of the mean squared error. The mean squared error measures the average squared difference between the estimate and the actual value assumed under the model, which is readily available from the updated (posterior) samples that are drawn in the Bayesian framework. Because mean squared error can be written as the sum of the squared standard error (SE) and the squared bias of an estimate, RMSE is seen to provide a measure of overall accuracy and takes into account the bias–variance tradeoff. For example, a model-based estimate with a small increase in bias but a large reduction in variance may be preferable to a direct estimate with presumably zero bias but a large variance that jeopardizes its statistical reliability.
- RRMSE—The relative RMSE is calculated as the ratio of the model-based and direct RMSEs (eMKF RMSE / direct RMSE). Generally, the direct estimate is assumed to be unbiased, in which case, direct RMSE = direct SE. However, in the case of the simulated NHIS subsample estimates, bias of direct estimates was estimated by taking the average of the difference between the 1,000 replicate subsample estimates and the true gold-standard estimate from the full NHIS sample. Smaller RRMSE values (less than 1) indicate that the model-based estimates result in improved overall estimate accuracy and precision.
- Standardized difference—Measures the difference between the model-based and direct estimates and is calculated as (MKF estimate – direct estimate) / direct SE. For example, standardized differences less than 1 indicate that the model-based estimates are within one SE of the corresponding direct estimates.
- Absolute 95% CI width—Illustrates the difference in uncertainty associated with the direct and model-based estimates.
- Percentage increase in equivalent sample size—Defined as 100 × [(1 / RRMSE) – 1], reflecting the relative increase in sample size that would be needed to obtain the same level of precision as the eMKF estimate.

### Applied analysis of 1999–2018 NHIS data to compare original MKF macro procedures with eMKF

Performance of the eMKF procedures was also compared with the performance of the original MKF procedures. For these comparisons, annual NHIS data for adults from 1999 to 2018 were used to estimate the prevalence of 10 health outcomes, covering a range of prevalence estimates and relative standard errors. Direct estimates and SEs for the last year of data, 2018, were design-based, using only the 2018 NHIS. MKF estimates and RMSEs for 2018 were model-based, using all 20 survey cycles from 1999 to 2018. Three sets of model-based estimates were calculated, gradually relaxing assumptions about sampling variances as well as the underlying trend model.

First, estimates and RMSEs based on the fully Bayesian linear trend model with fixed variances were obtained as in the earlier version of the MKF procedure and macro. Second, estimates and RMSEs based on the fully Bayesian linear trend model with random variances used the eMKF macro to account for the design-based variability in the sampling variances. Third, estimates and RMSEs based on cubic BMA also 1) used the eMKF macro to account for variability in the sampling variances and 2) were calculated as weighted posterior averages over samples drawn under the Bayesian framework from all seven available models: independent cubic, quadratic, and linear trends; common cubic, quadratic, and linear trends; and the intercepts-only (no trend) model.