# Introduction

Historically, the National Center for Health Statistics (NCHS) has published statistics on a variety of health outcomes by population subgroup, supporting efforts to assess and monitor health disparities across the U.S. population. With small sample or population sizes, however, direct estimates from NCHS data systems may not meet existing data presentation standards based on factors including sample size, width of confidence intervals, and design effects (in the context of survey estimates) (1,2). As a result, statistically reliable estimates may not be readily available for some subgroups, limiting the information available to quantify disparities among some subpopulations. Additionally, estimates for small subgroups may have large standard errors or confidence intervals, potentially leading to between-group differences that may be large in magnitude but not statistically significant.

Often, solutions to this challenge rely on combining (aggregating) data across time periods, larger subgroups, or geographic areas. However, this can adversely impact the timeliness, granularity, and relevance of information available for public health surveillance, research, and practice. Aggregating data over time or across larger groups can make it difficult to assess trends in disparities or to quantify within-group variation in health outcomes (as in differences in health by Hispanic-origin subgroup or by detailed urban–rural group within the larger metropolitan and nonmetropolitan categories). Another approach involves oversampling of certain groups in the survey design and sampling phase, to provide sufficient data to obtain statistically reliable direct estimates. However, this approach is costly and not feasible for all subpopulations that may be of interest.

Alternatively, model-based approaches such as small-domain estimation can be used to provide estimates of outcomes for small subgroups by borrowing strength across groups and over time (3–8). Although these model-based estimates may be less accurate than direct estimates when the latter are unbiased, such estimates are often more precise (that is, smaller standard errors or 95% confidence intervals) and can be especially useful when direct estimates for subgroups of interest do not meet existing statistical reliability standards. A recent report described enhancements to an existing small-domain estimation tool, the modified Kalman filter (MKF) (8–12).

## MKF

The earlier MKF procedure and accompanying SAS macro implemented a) mixed-effects models that assumed a linear trend over time in the true health state of each population subgroup (borrowing strength over time) and b) shared random effects that captured deviations from each group’s linear trend (borrowing strength across groups). Additionally, when two correlated health outcomes were considered, the earlier MKF procedure and macro allowed for model-based estimates from one outcome to inform the estimation of the other outcome (borrowing strength across health outcomes) (8–12).

Previous evaluations of the earlier MKF procedure and macro using simulated data demonstrated that, even in cases where estimated model parameters were subject to bias and estimation error, the MKF procedure improved overall estimate accuracy (as in root mean squared error) compared with direct estimates, at little cost other than computational time (9,10). Using cardiovascular health data from the National Health Interview Survey (NHIS), reductions in root mean squared error were shown to be equivalent to a sixfold increase in sample size, on average, across the different racial and ethnic groups considered (10).

Despite these gains in accuracy, precision, and efficiency (that is, percentage increase in equivalent sample size) with model-based estimates derived from the earlier MKF procedure, MKF has not been widely adopted to produce estimates for small subpopulations. This may be due, in part, to some features of the earlier MKF procedure and macro that limited their utility for analyses of NCHS data. Specifically, the earlier MKF procedure and macro were limited to cases where temporal trends were linear, time periods were equally spaced, and sample variances were assumed to be fixed or known. A recent report (8) describes several enhancements to the earlier MKF procedure and macro to make this modeling approach more accessible and relevant across various analytic scenarios commonly encountered with NCHS data. These enhancements are briefly described below.

## Enhancements to the MKF

The enhanced MKF procedure and macro accommodate nonlinear time trends, irregularly spaced time points, and random sampling variances for the underlying population subgroup means, rates, or proportions. Bayesian estimation in the enhanced MKF macro is implemented adaptably and transparently using PROC MCMC and related SAS 9.4 procedures, instead of relying on an associated external executable file with precompiled C code as with the original macro. Model averaging in the enhanced MKF macro, which renders predictions more robust to polynomial trend misspecification, uses a Bayesian mixture prior approach instead of a maximum likelihood-based approach. Various other features in the enhanced MKF macro also improve its functionality, flexibility, and usability relative to the earlier macro; a detailed description of the differences between the earlier and enhanced MKF procedures and macros is available elsewhere (8).

This report describes an evaluation of the performance of the enhanced modified Kalman filter (eMKF) macro for producing model-based estimates of health outcomes for small subgroups using NCHS data. Simulations were conducted to evaluate the performance of the eMKF procedure under different scenarios commonly encountered in analyses of NCHS data to quantify differences in accuracy and precision of model-based estimates relative to direct estimates. These simulated scenarios included: 1) a range of sample sizes, including very small subgroup samples; and 2) linear, quadratic, and cubic trends that are shared or unique across subgroups. Additionally, simulations under each of these scenarios examined outcomes that were more prevalent or less prevalent to determine whether accuracy and precision of model-based estimates may differ according to outcome prevalence. Finally, an applied analysis of NHIS data was conducted to compare model-based estimates obtained from the enhanced MKF macro and method with estimates derived from original MKF procedures (9).