# References

1 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. National Center for Health Statistics. Vital Health Stat 2(175). 2017.
2 Parker JD, Talih M, Irimata KE, Zhang G, Branum AM, Davis D, et al. National Center for Health Statistics data presentation standards for rates and counts. National Center for Health Statistics. Vital Health Stat 2(200). 2023. DOI: 10.15620/cdc:124368.
3 Franco C, Bell WR. Using American Community Survey data to improve estimates from smaller U.S. surveys through bivariate small area estimation models. J Surv Stat Methodol 10(1):225–47. 2022.
4 Sugasawa S, Kubokawa T. Small area estimation with mixed models: A review. Jpn J Stat Data Sci 3:693–720. 2020.
5 Polettini S. A generalised semiparametric Bayesian Fay–Herriot model for small area estimation shrinking both means and variances. Bayesian Anal 12(3):729–52. 2017.
6 Ha NS, Lahiri P, Parsons V. Methods and results for small area estimation using smoking data from the 2008 National Health Interview Survey. Stat Med 33(22):3932–45. 2014.24910281
7 Dass SC, Maiti T, Ren H, Sinha S. Confidence interval estimation of small area parameters shrinking both means and variances. Surv Methodol 38(2):173–87. 2012.
8 Talih M, Rossen LM, Patel P, Earp M, Parker JD. Technical guidance for using the modified Kalman filter in small-domain estimation at the National Center for Health Statistics. National Center for Health Statistics. Vital Health Stat 2(209). 2024. DOI: 10.15620/cdc/157496.
9 Elliott MN, McCaffrey DF, Finch BK, Klein DJ, Orr N, Beckett MK, Lurie N. Improving disparity estimates for rare racial/ethnic groups with trend estimation and Kalman filtering: An application to the National Health Interview Survey. Health Serv Res 44(5 Pt 1):1622–39. 2009.19656232
10 Lockwood JR, McCaffrey DF, Setodji CM, Elliott MN. Smoothing across time in repeated cross-sectional data. Stat Med 30(5):584–94. 2011.21290400
11 Setodji CM, Lockwood JR, McCaffrey DF, Elliott MN, Adams JL. The modified Kalman filter macro: User’s guide. RAND Technical Report No. TR-997-DHHS. 2011. Available from: https://www.rand.org/pubs/technical_reports/TR997.html.
12 Setodji CM, Lockwood JR, McCaffrey DF, Elliott MN, Adams JL. The modified Kalman filter macro: User’s guide. RAND Health Q 2(1):18. 2012.28083240
13 National Center for Health Statistics. National Health Interview Survey: 2019 questionnaire redesign. Available from: https://www.cdc.gov/nchs/nhis/2019_quest_redesign.htm.
14 Blewett LA, Rivera Drew JA, King ML, Williams KCW, Del Ponte N, Convey P. IPUMS Health Surveys: National Health Interview Series (NHIS): Version 7.2 [dataset]. Minneapolis, MN: IPUMS. 2022. Available from: 10.18128/D070.V7.2.
15 Akinbami LJ, Chen TC, Davy O, Ogden CL, Fink S, Clark J, et al. National Health and Nutrition Examination Survey, 2017–March 2020 prepandemic file: Sample design, estimation, and analytic guidelines. National Center for Health Statistics. Vital Health Stat 2(190). 2022. DOI: 10.15620/cdc:115434.
16 Bramlett MD, Dahlhamer JM, Bose J. Weighting procedures and bias assessment for the 2020 National Health Interview Survey. Hyattsville, MD: National Center for Health Statistics. 2021.