# Appendix. Supplemental Tables

Table I Comparison of direct estimates to MKF estimates for the proportion of adults with any functional limitations, by selected racial background and Hispanic ethnicity groups, from the fully Bayesian linear trend MKF model with fixed variances, the fully Bayesian linear trend MKF model with random variances, and the Bayesian model averaged cubic trend MKF model with random variances: United States, 2018

Population subgroup^1^ and estimation type^2^ | Estimate for 2018 | RMSE^3^ | 95% confidence interval^4^ | Standardized difference^5^ | Relative RMSE^6^ | Percent increase in equivalent sample size^7^
Non-Hispanic
American Indian and Alaska Native:
Direct estimate | 0.4694 | 0.0348 | (0.4012, 0.5375) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.4580 | 0.0163 | (0.4261, 0.4899) | -0.3259 | 0.4678 | 113.8
MKF estimate: Fully Bayesian linear trends with random variances | 0.4599 | 0.0177 | (0.4251, 0.4946) | -0.2734 | 0.5101 | 96.0
MKF estimate: BMA up to cubic trends with random variances | 0.4571 | 0.0155 | (0.4267, 0.4875) | -0.3526 | 0.4453 | †124.6
Asian, Indian origin:
Direct estimate | 0.1928 | 0.0275 | (0.1389, 0.2466) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1920 | 0.0136 | (0.1653, 0.2187) | -0.0286 | 0.4968 | 101.3
MKF estimate: Fully Bayesian linear trends with random variances | 0.1905 | 0.0145 | (0.1621, 0.2189) | -0.0837 | 0.5277 | 89.5
MKF estimate: BMA up to cubic trends with random variances | 0.1940 | 0.0130 | (0.1686, 0.2194) | 0.0443 | 0.4722 | †111.8
Black:
Direct estimate | 0.3604 | 0.0119 | (0.3370, 0.3839) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.3646 | 0.0090 | (0.3470, 0.3822) | 0.3464 | 0.7502 | 33.3
MKF estimate: Fully Bayesian linear trends with random variances | 0.3651 | 0.0091 | (0.3473, 0.3829) | 0.3862 | 0.7603 | 31.5
MKF estimate: BMA up to cubic trends with random variances | 0.3635 | 0.0088 | (0.3462, 0.3807) | 0.2526 | 0.7364 | †35.8
Chinese origin:
Direct estimate | 0.2151 | 0.0264 | (0.1633, 0.2669) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.2099 | 0.0137 | (0.1830, 0.2367) | -0.1973 | 0.5182 | 93.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.2082 | 0.0146 | (0.1795, 0.2368) | -0.2619 | 0.5523 | 81.1
MKF estimate: BMA up to cubic trends with random variances | 0.2121 | 0.0130 | (0.1867, 0.2375) | -0.1128 | 0.4910 | †103.7
Filipino origin:
Direct estimate | 0.3233 | 0.0365 | (0.2518, 0.3949) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.2841 | 0.0146 | (0.2555, 0.3128) | -1.0739 | 0.4005 | 149.7
MKF estimate: Fully Bayesian linear trends with random variances | 0.2854 | 0.0155 | (0.2550, 0.3159) | -1.0386 | 0.4253 | 135.1
MKF estimate: BMA up to cubic trends with random variances | 0.2835 | 0.0139 | (0.2562, 0.3109) | -1.0905 | 0.3819 | †161.8
White:
Direct estimate | 0.4155 | 0.0055 | (0.4047, 0.4263) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.4141 | 0.0050 | (0.4042, 0.4240) | -0.2525 | 0.9139 | 9.4
MKF estimate: Fully Bayesian linear trends with random variances | 0.4142 | 0.0051 | (0.4043, 0.4242) | -0.2338 | 0.9198 | 8.7
MKF estimate: BMA up to cubic trends with random variances | 0.4140 | 0.0050 | (0.4042, 0.4239) | -0.2689 | 0.9119 | †9.7
Hispanic
Cuban origin:
Direct estimate | 0.3495 | 0.0471 | (0.2572, 0.4418) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.2963 | 0.0156 | (0.2657, 0.3268) | -1.1313 | 0.3305 | 202.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.2962 | 0.0166 | (0.2637, 0.3287) | -1.1327 | 0.3517 | 184.3
MKF estimate: BMA up to cubic trends with random variances | 0.2970 | 0.0147 | (0.2681, 0.3258) | -1.1165 | 0.3130 | †219.5
Mexican or Mexican-American origin:
Direct estimate | 0.2632 | 0.0142 | (0.2355, 0.2910) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.2674 | 0.0099 | (0.2481, 0.2868) | 0.2966 | 0.6952 | 43.8
MKF estimate: Fully Bayesian linear trends with random variances | 0.2679 | 0.0100 | (0.2483, 0.2875) | 0.3289 | 0.7046 | 41.9
MKF estimate: BMA up to cubic trends with random variances | 0.2667 | 0.0097 | (0.2477, 0.2856) | 0.2414 | 0.6820 | †46.6
Puerto Rican origin:
Direct estimate | 0.3685 | 0.0354 | (0.2991, 0.4378) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.3798 | 0.0144 | (0.3516, 0.4081) | 0.3219 | 0.4071 | 145.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.3800 | 0.0151 | (0.3504, 0.4096) | 0.3277 | 0.4270 | 134.2
MKF estimate: BMA up to cubic trends with random variances | 0.3798 | 0.0137 | (0.3529, 0.4066) | 0.3202 | 0.3872 | †158.3
Other national origin:
Direct estimate | 0.2730 | 0.0185 | (0.2368, 0.3092) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.2670 | 0.0113 | (0.2449, 0.2891) | -0.3242 | 0.6109 | 63.7
MKF estimate: Fully Bayesian linear trends with random variances | 0.2664 | 0.0115 | (0.2439, 0.2889) | -0.3568 | 0.6221 | 60.7
MKF estimate: BMA up to cubic trends with random variances | 0.2683 | 0.0109 | (0.2469, 0.2898) | -0.2525 | 0.5926 | †68.7
All other population subgroups^1^
Direct estimate | 0.3533 | 0.0182 | (0.3177, 0.3890) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.3354 | 0.0116 | (0.3127, 0.3581) | -0.9860 | 0.6362 | 57.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.3340 | 0.0121 | (0.3104, 0.3576) | -1.0631 | 0.6624 | 51.0
MKF estimate: BMA up to cubic trends with random variances | 0.3378 | 0.0110 | (0.3163, 0.3594) | -0.8520 | 0.6051 | †65.3

… Category not applicable.

† Indicates cases where the cubic Bayesian model averaging (BMA) trend model improves on the fully Bayesian model with linear trends.

1 All population subgroup categories, except the last, are single-race categories. The category All other population subgroups includes the Pacific Islander non-Hispanic only population, other Asian non-Hispanic only subgroups, and multiracial populations.

2 Direct estimates for 2018 are design-based, using only the 2018 National Health Interview Survey (NHIS). Modified Kalman filter (MKF) estimates for 2018 are model-based, using all 20 survey cycles from 1999 to 2018. Estimates based on the fully Bayesian linear trend model with fixed variances are as in the earlier version of the MKF procedure and macro. Estimates based on the fully Bayesian linear trend model with random variances use the enhanced MKF (eMKF) macro to account for the design-based variability in the sampling variances. Estimates based on cubic BMA also use the eMKF macro to account for the variability in the sampling variances and are weighted updated (posterior) averages over the following models: independent cubic, quadratic, and linear trends; common cubic, quadratic, and linear trends; and the intercepts-only trend model.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 The standardized difference between the MKF-based and direct estimates is calculated as: (MKF estimate minus direct estimate) divided by direct SE.

6 Relative RMSE (RRMSE) is calculated as the ratio: MKF RMSE divided by direct RMSE.

7 The percentage increase in equivalent sample size is calculated as 100 times (1 divided by RRMSE minus 1) and indicates the mean percentage increase in the equivalent sample size of 2018-only estimates due to the selected MKF model.

NOTES: All estimates shown are crude estimates, not adjusted for age. Any functional limitations is defined as having any difficulty doing one or more of the following activities by oneself without any special equipment: going out to activities like shopping, movies, or sporting events; participating in social activities (such as visiting friends, attending clubs and meetings, and going to parties); doing things to relax at home or for leisure (as in reading, watching TV, sewing, or listening to music); walking one-quarter of a mile (or three city blocks); climbing 10 steps without resting; standing for 2 hours; sitting for 2 hours; stooping, bending, or kneeling; reaching over one’s head; using one’s fingers to grasp or handle small objects; lifting or carrying a 10-pound object (such as a full bag of groceries); and pushing or pulling a large object (such as a living room chair).

SOURCE: National Center for Health Statistics, National Health Interview Surveys, 2018.

Table II Comparison of direct estimates to MKF estimates for the proportion of adults with hypertension, by selected racial background and Hispanic ethnicity groups, from the fully Bayesian linear trend MKF model with fixed variances, the fully Bayesian linear trend MKF model with random variances, and the Bayesian model averaged cubic trend MKF model with random variances: United States, 2018

Population subgroup^1^ and estimation type^2^ | Estimate for 2018 | RMSE^3^ | 95% confidence interval^4^ | Standardized difference^5^ | Relative RMSE^6^ | Percent increase in equivalent sample size^7^
Non-Hispanic
American Indian and Alaska Native:
Direct estimate | 0.2567 | 0.0350 | (0.1881, 0.3253) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.3072 | 0.0123 | (0.2830, 0.3313) | 1.4410 | 0.3521 | 184.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.3072 | 0.0122 | (0.2832, 0.3312) | 1.4425 | 0.3497 | 186.0
MKF estimate: BMA up to cubic trends with random variances | 0.3084 | 0.0110 | (0.2868, 0.3300) | 1.4752 | 0.3148 | †217.7
Asian, Indian origin:
Direct estimate | 0.1812 | 0.0255 | (0.1311, 0.2313) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1543 | 0.0092 | (0.1361, 0.1724) | -1.0542 | 0.3621 | 176.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.1543 | 0.0092 | (0.1361, 0.1724) | -1.0546 | 0.3618 | 176.4
MKF estimate: BMA up to cubic trends with random variances | 0.1534 | 0.0083 | (0.1371, 0.1696) | -1.0900 | 0.3250 | †207.7
Black:
Direct estimate | 0.3314 | 0.0116 | (0.3087, 0.3540) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.3434 | 0.0063 | (0.3310, 0.3558) | 1.0443 | 0.5471 | 82.8
MKF estimate: Fully Bayesian linear trends with random variances | 0.3433 | 0.0063 | (0.3310, 0.3557) | 1.0370 | 0.5465 | 83.0
MKF estimate: BMA up to cubic trends with random variances | 0.3414 | 0.0059 | (0.3298, 0.3530) | 0.8658 | 0.5127 | †95.0
Chinese origin:
Direct estimate | 0.1530 | 0.0272 | (0.0996, 0.2063) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1754 | 0.0094 | (0.1569, 0.1938) | 0.8223 | 0.3454 | 189.5
MKF estimate: Fully Bayesian linear trends with random variances | 0.1754 | 0.0094 | (0.1570, 0.1938) | 0.8242 | 0.3456 | 189.4
MKF estimate: BMA up to cubic trends with random variances | 0.1768 | 0.0086 | (0.1600, 0.1936) | 0.8741 | 0.3147 | †217.8
Filipino origin:
Direct estimate | 0.2830 | 0.0324 | (0.2194, 0.3466) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.3016 | 0.0120 | (0.2780, 0.3252) | 0.5746 | 0.3708 | 169.7
MKF estimate: Fully Bayesian linear trends with random variances | 0.3014 | 0.0118 | (0.2782, 0.3246) | 0.5674 | 0.3647 | 174.2
MKF estimate: BMA up to cubic trends with random variances | 0.2962 | 0.0098 | (0.2769, 0.3154) | 0.4072 | 0.3027 | †230.4
White:
Direct estimate | 0.2874 | 0.0043 | (0.2789, 0.2959) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.2902 | 0.0035 | (0.2834, 0.2971) | 0.6531 | 0.8062 | 24.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.2902 | 0.0035 | (0.2833, 0.2971) | 0.6455 | 0.8074 | 23.9
MKF estimate: BMA up to cubic trends with random variances | 0.2893 | 0.0034 | (0.2826, 0.2960) | 0.4406 | 0.7859 | †27.2
Hispanic
Cuban origin:
Direct estimate | 0.2708 | 0.0391 | (0.1941, 0.3475) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.2927 | 0.0116 | (0.2700, 0.3155) | 0.5599 | 0.2966 | 237.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.2929 | 0.0116 | (0.2702, 0.3155) | 0.5636 | 0.2958 | 238.1
MKF estimate: BMA up to cubic trends with random variances | 0.2956 | 0.0100 | (0.2761, 0.3152) | 0.6341 | 0.2553 | †291.7
Mexican or Mexican-American origin:
Direct estimate | 0.1902 | 0.0125 | (0.1657, 0.2147) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1875 | 0.0061 | (0.1755, 0.1994) | -0.2191 | 0.4882 | 104.8
MKF estimate: Fully Bayesian linear trends with random variances | 0.1875 | 0.0061 | (0.1755, 0.1995) | -0.2140 | 0.4893 | 104.4
MKF estimate: BMA up to cubic trends with random variances | 0.1891 | 0.0059 | (0.1776, 0.2006) | -0.0877 | 0.4680 | †113.7
Puerto Rican origin:
Direct estimate | 0.3089 | 0.0307 | (0.2487, 0.3690) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.2651 | 0.0093 | (0.2468, 0.2833) | -1.4268 | 0.3034 | 229.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.2651 | 0.0093 | (0.2469, 0.2833) | -1.4265 | 0.3024 | 230.7
MKF estimate: BMA up to cubic trends with random variances | 0.2653 | 0.0084 | (0.2489, 0.2816) | -1.4201 | 0.2720 | †267.6
Other national origin:
Direct estimate | 0.1713 | 0.0169 | (0.1382, 0.2044) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1788 | 0.0075 | (0.1640, 0.1936) | 0.4481 | 0.4468 | 123.8
MKF estimate: Fully Bayesian linear trends with random variances | 0.1789 | 0.0075 | (0.1642, 0.1937) | 0.4536 | 0.4458 | 124.3
MKF estimate: BMA up to cubic trends with random variances | 0.1825 | 0.0070 | (0.1688, 0.1963) | 0.6685 | 0.4164 | †140.2
All other population subgroups^1^
Direct estimate | 0.2398 | 0.0153 | (0.2098, 0.2698) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.2369 | 0.0074 | (0.2223, 0.2514) | -0.1917 | 0.4847 | 106.3
MKF estimate: Fully Bayesian linear trends with random variances | 0.2368 | 0.0074 | (0.2223, 0.2514) | -0.1930 | 0.4852 | 106.1
MKF estimate: BMA up to cubic trends with random variances | 0.2362 | 0.0069 | (0.2227, 0.2498) | -0.2332 | 0.4526 | †120.9

… Category not applicable.

† Indicates cases where the cubic Bayesian model averaging (BMA) trend model improves on the fully Bayesian model with linear trends.

1 All population subgroup categories, except the last, are single-race categories. The category All other population subgroups includes the Pacific Islander non-Hispanic only population, other Asian non-Hispanic only subgroups, and multiracial populations.

2 Direct estimates for 2018 are design-based, using only the 2018 National Health Interview Survey (NHIS). Modified Kalman filter (MKF) estimates for 2018 are model-based, using all 20 survey cycles from 1999 to 2018. Estimates based on the fully Bayesian linear trend model with fixed variances are as in the earlier version of the MKF procedure and macro. Estimates based on the fully Bayesian linear trend model with random variances use the enhanced MKF (eMKF) macro to account for the design-based variability in the sampling variances. Estimates based on cubic BMA also use the eMKF macro to account for the variability in the sampling variances and are weighted updated (posterior) averages over the following models: independent cubic, quadratic, and linear trends; common cubic, quadratic, and linear trends; and the intercepts-only trend model.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 The standardized difference between the MKF-based and direct estimates is calculated as: (MKF estimate minus direct estimate) divided by direct SE.

6 Relative RMSE (RRMSE) is calculated as the ratio: MKF RMSE divided by direct RMSE.

7 The percentage increase in equivalent sample size is calculated as 100 times (1 divided by RRMSE minus 1) and indicates the mean percentage increase in the equivalent sample size of 2018-only estimates due to the selected MKF model.

NOTES: All estimates shown are crude estimates, not adjusted for age. In separate questions, respondents were asked if they had ever been told by a doctor or other health professional that they had hypertension (or high blood pressure), and if they had been told on two or more different visits that they had hypertension or high blood pressure. Respondents are classified as hypertensive (or with high blood pressure) only if they answered yes to both questions.

SOURCE: National Center for Health Statistics, National Health Interview Surveys, 2018.

Table III Comparison of direct estimates to MKF estimates for the proportion of adults ever diagnosed with asthma, by selected racial background and Hispanic ethnicity groups, from the fully Bayesian linear trend MKF model with fixed variances, the fully Bayesian linear trend MKF model with random variances, and the Bayesian model averaged cubic trend MKF model with random variances: United States, 2018

Population subgroup^1^ and estimation type^2^ | Estimate for 2018 | RMSE^3^ | 95% confidence interval^4^ | Standardized difference^5^ | Relative RMSE^6^ | Percent increase in equivalent sample size^7^
Non-Hispanic
American Indian and Alaska Native:
Direct estimate | 0.1713 | 0.0316 | (0.1093, 0.2333) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1655 | 0.0114 | (0.1432, 0.1879) | -0.1818 | 0.3606 | 177.3
MKF estimate: Fully Bayesian linear trends with random variances | 0.1655 | 0.0113 | (0.1434, 0.1876) | -0.1814 | 0.3565 | 180.5
MKF estimate: BMA up to cubic trends with random variances | 0.1655 | 0.0108 | (0.1444, 0.1866) | -0.1825 | 0.3403 | †193.9
Asian, Indian origin:
Direct estimate | 0.0365 | 0.0092 | (0.0184, 0.0547) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0523 | 0.0071 | (0.0383, 0.0663) | 1.7007 | 0.7716 | 29.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.0524 | 0.0071 | (0.0385, 0.0664) | 1.7179 | 0.7698 | 29.9
MKF estimate: BMA up to cubic trends with random variances | 0.0536 | 0.0070 | (0.0399, 0.0673) | 1.8489 | 0.7565 | †32.2
Black:
Direct estimate | 0.1476 | 0.0089 | (0.1302, 0.1650) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1505 | 0.0062 | (0.1384, 0.1627) | 0.3279 | 0.6964 | 43.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.1505 | 0.0062 | (0.1384, 0.1626] | 0.3229 | 0.6951 | 43.9
MKF estimate: BMA up to cubic trends with random variances | 0.1493 | 0.0060 | (0.1376, 0.1610) | 0.1884 | 0.6723 | †48.7
Chinese origin:
Direct estimate | *0.0351 | 0.0139 | (0.0079, 0.0622) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0615 | 0.0085 | (0.0449, 0.0781) | 1.9052 | 0.6111 | 63.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.0617 | 0.0084 | (0.0452, 0.0781) | 1.9186 | 0.6058 | 65.1
MKF estimate: BMA up to cubic trends with random variances | 0.0628 | 0.0082 | (0.0468, 0.0788) | 1.9996 | 0.5892 | †69.7
Filipino origin:
Direct estimate | 0.1307 | 0.0280 | (0.0758, 0.1857) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1418 | 0.0108 | (0.1206, 0.1629) | 0.3935 | 0.3850 | 159.7
MKF estimate: Fully Bayesian linear trends with random variances | 0.1416 | 0.0106 | (0.1208, 0.1624) | 0.3868 | 0.3787 | 164.1
MKF estimate: BMA up to cubic trends with random variances | 0.1405 | 0.0100 | (0.1208, 0.1602) | 0.3482 | 0.3581 | †179.3
White:
Direct estimate | 0.1375 | 0.0032 | (0.1313, 0.1438) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1383 | 0.0029 | (0.1326, 0.1441) | 0.2471 | 0.9177 | 9.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.1383 | 0.0029 | (0.1326, 0.1441) | 0.2509 | 0.9206 | 8.6
MKF estimate: BMA up to cubic trends with random variances | 0.1383 | 0.0029 | (0.1326, 0.1441) | 0.2449 | 0.9193 | 8.8
Hispanic
Cuban origin:
Direct estimate | 0.1295 | 0.0311 | (0.0687, 0.1904) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1248 | 0.0108 | (0.1037, 0.1459) | -0.1532 | 0.3465 | 188.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.1247 | 0.0106 | (0.1038, 0.1456) | -0.1567 | 0.3429 | 191.6
MKF estimate: BMA up to cubic trends with random variances | 0.1234 | 0.0099 | (0.1040, 0.1429) | -0.1966 | 0.3192 | †213.3
Mexican or Mexican-American origin:
Direct estimate | 0.0866 | 0.0079 | (0.0712, 0.1021) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0934 | 0.0059 | (0.0819, 0.1049) | 0.8632 | 0.7435 | 34.5
MKF estimate: Fully Bayesian linear trends with random variances | 0.0934 | 0.0059 | (0.0819, 0.1049) | 0.8633 | 0.7434 | 34.5
MKF estimate: BMA up to cubic trends with random variances | 0.0933 | 0.0058 | (0.0819, 0.1046) | 0.8433 | 0.7330 | †36.4
Puerto Rican origin:
Direct estimate | 0.2280 | 0.0286 | (0.1720, 0.2841) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.2263 | 0.0104 | (0.2059, 0.2467) | -0.0606 | 0.3642 | 174.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.2264 | 0.0103 | (0.2061, 0.2466) | -0.0587 | 0.3610 | 177.0
MKF estimate: BMA up to cubic trends with random variances | 0.2267 | 0.0098 | (0.2074, 0.2460) | -0.0474 | 0.3438 | †190.9
Other national origin:
Direct estimate | 0.1308 | 0.0131 | (0.1051, 0.1564) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1171 | 0.0077 | (0.1020, 0.1321) | -1.0474 | 0.5882 | 70.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.1171 | 0.0076 | (0.1021, 0.1320) | -1.0473 | 0.5839 | 71.3
MKF estimate: BMA up to cubic trends with random variances | 0.1175 | 0.0074 | (0.1030, 0.1321) | -1.0122 | 0.5682 | †76.0
All other population subgroups^1^
Direct estimate | 0.1881 | 0.0171 | (0.1545, 0.2216) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1532 | 0.0083 | (0.1369, 0.1696) | -2.0369 | 0.4872 | 105.3
MKF estimate: Fully Bayesian linear trends with random variances | 0.1531 | 0.0083 | (0.1369, 0.1693) | -2.0412 | 0.4825 | 107.3
MKF estimate: BMA up to cubic trends with random variances | 0.1527 | 0.0080 | (0.1369, 0.1685) | -2.0662 | 0.4697 | †112.9

… Category not applicable.

† Indicates cases where the cubic Bayesian model averaging (BMA) trend model improves on the fully Bayesian model with linear trends.

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 All population subgroup categories, except the last, are single-race categories. The category All other population subgroups includes the Pacific Islander non-Hispanic only population, other Asian non-Hispanic only subgroups, and multiracial populations.

2 Direct estimates for 2018 are design-based, using only the 2018 National Health Interview Survey (NHIS). Modified Kalman filter (MKF) estimates for 2018 are model-based, using all 20 survey cycles from 1999 to 2018. Estimates based on the fully Bayesian linear trend model with fixed variances are as in the earlier version of the MKF procedure and macro. Estimates based on the fully Bayesian linear trend model with random variances use the enhanced MKF (eMKF) macro to account for the design-based variability in the sampling variances. Estimates based on cubic BMA also use the eMKF macro to account for the variability in the sampling variances and are weighted updated (posterior) averages over the following models: independent cubic, quadratic, and linear trends; common cubic, quadratic, and linear trends; and the intercepts-only trend model.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 The standardized difference between the MKF-based and direct estimates is calculated as: (MKF estimate minus direct estimate) divided by direct SE.

6 Relative RMSE (RRMSE) is calculated as the ratio: (MKF RMSE divided by direct RMSE.

7 The percentage increase in equivalent sample size is calculated as 100 times (1 divided by RRMSE minus 1) and indicates the mean percentage increase in the equivalent sample size of 2018-only estimates due to the selected MKF model.

NOTES: All estimates shown are crude estimates, not adjusted for age. Respondents were asked if they had ever been told by a doctor or other health professional that they had asthma.

SOURCE: National Center for Health Statistics, National Health Interview Surveys, 2018.

Table IV Comparison of direct estimates to MKF estimates for the proportion of adults with any heart disease, by selected racial background and Hispanic ethnicity groups, from the fully Bayesian linear trend MKF model with fixed variances, the fully Bayesian linear trend MKF model with random variances, and the Bayesian model averaged cubic trend MKF model with random variances: United States, 2018

Population subgroup^1^ and estimation type^2^ | Estimate for 2018 | RMSE^3^ | 95% confidence interval^4^ | Standardized difference^5^ | Relative RMSE^6^ | Percent increase in equivalent sample size^7^
Non-Hispanic
American Indian and Alaska Native:
Direct estimate | 0.1456 | 0.0271 | (0.0924, 0.1988) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1287 | 0.0081 | (0.1128, 0.1446) | -0.6227 | 0.2990 | 234.4
MKF estimate: Fully Bayesian linear trends with random variances | 0.1286 | 0.0081 | (0.1128, 0.1445) | -0.6233 | 0.2984 | 235.1
MKF estimate: BMA up to cubic trends with random variances | 0.1269 | 0.0082 | (0.1108, 0.1429) | -0.6887 | 0.3013 | 231.9
Asian, Indian origin:
Direct estimate | 0.0532 | 0.0115 | (0.0308, 0.0757) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0394 | 0.0051 | (0.0294, 0.0494) | -1.2086 | 0.4455 | 124.5
MKF estimate: Fully Bayesian linear trends with random variances | 0.0393 | 0.0051 | (0.0292, 0.0493) | -1.2179 | 0.4481 | 123.2
MKF estimate: BMA up to cubic trends with random variances | 0.0346 | 0.0044 | (0.0260, 0.0432) | -1.6263 | 0.3821 | †161.7
Black:
Direct estimate | 0.0981 | 0.0062 | (0.0861, 0.1102) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1008 | 0.0031 | (0.0948, 0.1068) | 0.4258 | 0.4973 | 101.1
MKF estimate: Fully Bayesian linear trends with random variances | 0.1007 | 0.0031 | (0.0947, 0.1067) | 0.4172 | 0.4983 | 100.7
MKF estimate: BMA up to cubic trends with random variances | 0.0997 | 0.0037 | (0.0925, 0.1070] | 0.2600 | 0.6032 | 65.8
Chinese origin:
Direct estimate | 0.0638 | 0.0171 | (0.0302, 0.0974) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0577 | 0.0051 | (0.0477, 0.0677) | -0.3575 | 0.2986 | 234.9
MKF estimate: Fully Bayesian linear trends with random variances | 0.0577 | 0.0051 | (0.0476, 0.0677) | -0.3586 | 0.2996 | 233.8
MKF estimate: BMA up to cubic trends with random variances | 0.0563 | 0.0054 | (0.0457, 0.0669) | -0.4358 | 0.3154 | 217.1
Filipino origin:
Direct estimate | 0.0951 | 0.0192 | (0.0574, 0.1328) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0837 | 0.0060 | (0.0720, 0.0955) | -0.5913 | 0.3117 | 220.8
MKF estimate: Fully Bayesian linear trends with random variances | 0.0837 | 0.0060 | (0.0720, 0.0954) | -0.5923 | 0.3117 | 220.8
MKF estimate: BMA up to cubic trends with random variances | 0.0811 | 0.0059 | (0.0696, 0.0926) | -0.7284 | 0.3051 | †227.8
White:
Direct estimate | 0.1429 | 0.0031 | (0.1368, 0.1491) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1404 | 0.0021 | (0.1362, 0.1445) | -0.8115 | 0.6739 | 48.4
MKF estimate: Fully Bayesian linear trends with random variances | 0.1404 | 0.0021 | (0.1362, 0.1446) | -0.8054 | 0.6827 | 46.5
MKF estimate: BMA up to cubic trends with random variances | 0.1400 | 0.0023 | (0.1356, 0.1445) | -0.9124 | 0.7295 | 37.1
Hispanic
Cuban origin:
Direct estimate | 0.0820 | 0.0236 | (0.0357, 0.1283) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0889 | 0.0064 | (0.0763, 0.1015) | 0.2929 | 0.2713 | 268.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.0889 | 0.0064 | (0.0764, 0.1015) | 0.2944 | 0.2709 | 269.1
MKF estimate: BMA up to cubic trends with random variances | 0.0890 | 0.0064 | (0.0764, 0.1015) | 0.2949 | 0.2712 | 268.7
Mexican or Mexican-American origin:
Direct estimate | 0.0634 | 0.0067 | (0.0503, 0.0764) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0602 | 0.0030 | (0.0542, 0.0661) | -0.4768 | 0.4564 | 119.1
MKF estimate: Fully Bayesian linear trends with random variances | 0.0602 | 0.0031 | (0.0542, 0.0662) | -0.4770 | 0.4589 | 117.9
MKF estimate: BMA up to cubic trends with random variances | 0.0601 | 0.0035 | (0.0532, 0.0671) | -0.4832 | 0.5319 | 88.0
Puerto Rican origin:
Direct estimate | 0.1267 | 0.0246 | (0.0786, 0.1749) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1125 | 0.0056 | (0.1014, 0.1235) | -0.5813 | 0.2298 | 335.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.1124 | 0.0057 | (0.1013, 0.1235) | -0.5842 | 0.2303 | 334.2
MKF estimate: BMA up to cubic trends with random variances | 0.1104 | 0.0058 | (0.0990, 0.1219) | -0.6633 | 0.2379 | 320.3
Other national origin:
Direct estimate | 0.0553 | 0.0079 | (0.0398, 0.0708) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0564 | 0.0037 | (0.0490, 0.0637) | 0.1370 | 0.4720 | 111.9
MKF estimate: Fully Bayesian linear trends with random variances | 0.0564 | 0.0037 | (0.0491, 0.0637) | 0.1407 | 0.4727 | 111.6
MKF estimate: BMA up to cubic trends with random variances | 0.0573 | 0.0045 | (0.0486, 0.0660) | 0.2574 | 0.5643 | 77.2
All other population subgroups^1^
Direct estimate | 0.1186 | 0.0123 | (0.0946, 0.1427) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0946 | 0.0044 | (0.0859, 0.1032) | -1.9627 | 0.3589 | 178.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.0946 | 0.0044 | (0.0860, 0.1032) | -1.9612 | 0.3588 | 178.7
MKF estimate: BMA up to cubic trends with random variances | 0.0950 | 0.0044 | (0.0863, 0.1036) | -1.9312 | 0.3611 | 176.9

… Category not applicable.

† Indicates cases where the cubic Bayesian model averaging (BMA) trend model improves on the fully Bayesian model with linear trends.

1 All population subgroup categories, except the last, are single-race categories. The category All other population subgroups includes the Pacific Islander non-Hispanic only population, other Asian non-Hispanic only subgroups, and multiracial populations.

2 Direct estimates for 2018 are design-based, using only the 2018 National Health Interview Survey (NHIS). Modified Kalman filter (MKF) estimates for 2018 are model-based, using all 20 survey cycles from 1999 to 2018. Estimates based on the fully Bayesian linear trend model with fixed variances are as in the earlier version of the MKF procedure and macro. Estimates based on the fully Bayesian linear trend model with random variances use the enhanced MKF (eMKF) macro to account for the design-based variability in the sampling variances. Estimates based on cubic BMA also use the eMKF macro to account for the variability in the sampling variances and are weighted updated (posterior) averages over the following models: independent cubic, quadratic, and linear trends; common cubic, quadratic, and linear trends; and the intercepts-only trend model.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 The standardized difference between the MKF-based and direct estimates is calculated as: MKF estimate minus direct estimate) divided by direct SE.

6 Relative RMSE (RRMSE) is calculated as the ratio: MKF RMSE divided by direct RMSE.

7 The percentage increase in equivalent sample size is calculated as 100 times (1 divided by RRMSE minus 1) and indicates the mean percentage increase in the equivalent sample size of 2018-only estimates due to the selected MKF model.

NOTES: All estimates shown are crude estimates, not adjusted for age. In separate questions, respondents were asked if they had ever been told by a doctor or other health professional that they had coronary heart disease, angina (or angina pectoris), heart attack (or myocardial infarction), or any other heart condition or disease not already mentioned. Any heart disease is defined as coronary heart disease, angina, heart attack, or any other heart condition or disease.

SOURCE: National Center for Health Statistics, National Health Interview Surveys, 2018.

Table V Comparison of direct estimates to MKF estimates for the proportion of adults reporting a history of cancer, by selected racial background and Hispanic ethnicity groups, from the fully Bayesian linear trend MKF model with fixed variances, the fully Bayesian linear trend MKF model with random variances, and the Bayesian model averaged cubic trend MKF model with random variances: United States, 2018

Population subgroup^1^ and estimation type^2^ | Estimate for 2018 | RMSE^3^ | 95% confidence interval^4^ | Standardized difference^5^ | Relative RMSE^6^ | Percent increase in equivalent sample size^7^
Non-Hispanic
American Indian and Alaska Native:
Direct estimate | *0.0768 | 0.0247 | (0.0283, 0.1253) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0497 | 0.0067 | (0.0367, 0.0628) | -1.0935 | 0.2694 | 271.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.0498 | 0.0067 | (0.0367, 0.0628) | -1.0921 | 0.2690 | 271.7
MKF estimate: BMA up to cubic trends with random variances | 0.0524 | 0.0064 | (0.0398, 0.0651) | -0.9835 | 0.2607 | †283.6
Asian, Indian origin:
Direct estimate | 0.0233 | 0.0091 | (0.0054, 0.0411) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0102 | 0.0032 | (0.0040, 0.0164) | -1.4383 | 0.3498 | 185.9
MKF estimate: Fully Bayesian linear trends with random variances | 0.0103 | 0.0032 | (0.0040, 0.0165) | -1.4321 | 0.3518 | 184.3
MKF estimate: BMA up to cubic trends with random variances | 0.0142 | 0.0044 | (0.0056, 0.0227) | -1.0014 | 0.4787 | 108.9
Black:
Direct estimate | 0.0509 | 0.0044 | (0.0424, 0.0595) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0506 | 0.0023 | (0.0461, 0.0550) | -0.0891 | 0.5167 | 93.5
MKF estimate: Fully Bayesian linear trends with random variances | 0.0505 | 0.0023 | (0.0461, 0.0550) | -0.0937 | 0.5208 | 92.0
MKF estimate: BMA up to cubic trends with random variances | 0.0499 | 0.0030 | (0.0440, 0.0558) | -0.2448 | 0.6902 | 44.9
Chinese origin:
Direct estimate | 0.0308 | 0.0104 | (0.0104, 0.0512) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0323 | 0.0043 | (0.0239, 0.0407) | 0.1448 | 0.4115 | 143.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.0323 | 0.0043 | (0.0239, 0.0408) | 0.1448 | 0.4142 | 141.4
MKF estimate: BMA up to cubic trends with random variances | 0.0299 | 0.0051 | (0.0198, 0.0400) | -0.0899 | 0.4933 | 102.7
Filipino origin:
Direct estimate | 0.0698 | 0.0171 | (0.0363, 0.1033) | ~~ | ~~ | --
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0524 | 0.0053 | (0.0421, 0.0627) | -1.0192 | 0.3075 | 225.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.0523 | 0.0052 | (0.0420, 0.0626) | -1.0222 | 0.3067 | 226.1
MKF estimate: BMA up to cubic trends with random variances | 0.0429 | 0.0056 | (0.0318, 0.0539) | -1.5733 | 0.3304 | 202.7
White:
Direct estimate | 0.1239 | 0.0027 | (0.1186, 0.1292) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1235 | 0.0018 | (0.1201, 0.1269) | -0.1576 | 0.6447 | 55.1
MKF estimate: Fully Bayesian linear trends with random variances | 0.1235 | 0.0018 | (0.1200, 0.1270) | -0.1485 | 0.6518 | 53.4
MKF estimate: BMA up to cubic trends with random variances | 0.1230 | 0.0022 | (0.1186, 0.1274) | -0.3284 | 0.8236 | 21.4
Hispanic
Cuban origin:
Direct estimate | *0.0554 | 0.0210 | (0.0143, 0.0965) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0456 | 0.0059 | (0.0341, 0.0571) | -0.4669 | 0.2806 | 256.4
MKF estimate: Fully Bayesian linear trends with random variances | 0.0456 | 0.0059 | (0.0340, 0.0572) | -0.4666 | 0.2812 | 255.6
MKF estimate: BMA up to cubic trends with random variances | 0.0487 | 0.0062 | (0.0365, 0.0609) | -0.3198 | 0.2967 | 237.0
Mexican or Mexican-American origin:
Direct estimate | 0.0270 | 0.0036 | (0.0200, 0.0340) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0294 | 0.0021 | (0.0253, 0.0334) | 0.6617 | 0.5781 | 73.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.0294 | 0.0021 | (0.0253, 0.0335) | 0.6614 | 0.5839 | 71.3
MKF estimate: BMA up to cubic trends with random variances | 0.0302 | 0.0028 | (0.0248, 0.0356) | 0.8869 | 0.7702 | 29.8
Puerto Rican origin:
Direct estimate | *0.0446 | 0.0151 | (0.0150, 0.0743) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0539 | 0.0049 | (0.0442, 0.0635) | 0.6102 | 0.3247 | 208.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.0538 | 0.0049 | (0.0442, 0.0635) | 0.6071 | 0.3255 | 207.2
MKF estimate: BMA up to cubic trends with random variances | 0.0522 | 0.0055 | (0.0414, 0.0630) | 0.4981 | 0.3653 | 173.7
Other national origin:
Direct estimate | 0.0324 | 0.0056 | (0.0215, 0.0434) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0300 | 0.0027 | (0.0247, 0.0354) | -0.4324 | 0.4871 | 105.3
MKF estimate: Fully Bayesian linear trends with random variances | 0.0300 | 0.0027 | (0.0247, 0.0354) | -0.4300 | 0.4877 | 105.0
MKF estimate: BMA up to cubic trends with random variances | 0.0314 | 0.0036 | (0.0244, 0.0384) | -0.1778 | 0.6392 | 56.4
All other population subgroups^1^
Direct estimate | 0.0523 | 0.0070 | (0.0386, 0.0660) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0579 | 0.0036 | (0.0508, 0.0649) | 0.7999 | 0.5151 | 94.1
MKF estimate: Fully Bayesian linear trends with random variances | 0.0578 | 0.0036 | (0.0508, 0.0649) | 0.7962 | 0.5174 | 93.3
MKF estimate: BMA up to cubic trends with random variances | 0.0569 | 0.0042 | (0.0486, 0.0652) | 0.6579 | 0.6071 | 64.7

* Estimate does not meet National Center for Health Statistics standards of reliability.

… Category not applicable.

† Indicates cases where the cubic Bayesian model averaging (BMA) trend model improves on the fully Bayesian model with linear trends.

1 All population subgroup categories, except the last, are single-race categories. The category All other population subgroups includes the Pacific Islander non-Hispanic only population, other Asian non-Hispanic only subgroups, and multiracial populations.

2 Direct estimates for 2018 are design-based, using only the 2018 National Health Interview Survey (NHIS). Modified Kalman filter (MKF) estimates for 2018 are model-based, using all 20 survey cycles from 1999 to 2018. Estimates based on the fully Bayesian linear trend model with fixed variances are as in the earlier version of the MKF procedure and macro. Estimates based on the fully Bayesian linear trend model with random variances use the enhanced MKF (eMKF) macro to account for the design-based variability in the sampling variances. Estimates based on cubic BMA also use the eMKF macro to account for the variability in the sampling variances and are weighted updated (posterior) averages over the following models: independent cubic, quadratic, and linear trends; common cubic, quadratic, and linear trends; and the intercepts-only trend model.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 The standardized difference between the MKF-based and direct estimates is calculated as: (MKF estimate minus direct estimate) divided by direct SE.

6 Relative RMSE (RRMSE) is calculated as the ratio: MKF RMSE divided by direct RMSE.

7 The percentage increase in equivalent sample size is calculated as 100 times (1 divided by RRMSE minus 1) and indicates the mean percentage increase in the equivalent sample size of 2018-only estimates due to the selected MKF model.

NOTES: All estimates shown are crude estimates, not adjusted for age. Respondents were asked if they had ever been told by a doctor or other health professional that they had a cancer or malignancy of any kind.

SOURCE: National Center for Health Statistics, National Health Interview Surveys, 2018.

Table VI Comparison of direct estimates to MKF estimates for the proportion of adults who are current smokers, by selected racial background and Hispanic ethnicity groups, from the fully Bayesian linear trend MKF model with fixed variances, the fully Bayesian linear trend MKF model with random variances, and the Bayesian model averaged cubic trend MKF model with random variances: United States, 2018

Population subgroup^1^ and estimation type^2^ | Estimate for 2018 | RMSE^3^ | 95% confidence interval^4^ | Standardized difference^5^ | Relative RMSE^6^ | Percent increase in equivalent sample size^7^
Non-Hispanic
American Indian and Alaska Native:
Direct estimate | 0.2265 | 0.0542 | (0.1202, 0.3328) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.2474 | 0.0161 | (0.2159, 0.2789) | 0.3849 | 0.2964 | 237.4
MKF estimate: Fully Bayesian linear trends with random variances | 0.2474 | 0.0160 | (0.2159, 0.2788) | 0.3847 | 0.2958 | 238.1
MKF estimate: BMA up to cubic trends with random variances | 0.2559 | 0.0133 | (0.2298, 0.2820) | 0.5423 | 0.2452 | †307.8
Asian, Indian origin:
Direct estimate | 0.0383 | 0.0093 | (0.0201, 0.0565) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0333 | 0.0065 | (0.0206, 0.0461) | -0.5392 | 0.7023 | 42.4
MKF estimate: Fully Bayesian linear trends with random variances | 0.0334 | 0.0065 | (0.0206, 0.0462) | -0.5350 | 0.7038 | 42.1
MKF estimate: BMA up to cubic trends with random variances | 0.0297 | 0.0063 | (0.0174, 0.0420) | -0.9311 | 0.6784 | †47.4
Black:
Direct estimate | 0.1456 | 0.0088 | (0.1283, 0.1629) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1501 | 0.0059 | (0.1387, 0.1616) | 0.5146 | 0.6640 | 50.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.1501 | 0.0059 | (0.1387, 0.1616) | 0.5125 | 0.6631 | 50.8
MKF estimate: BMA up to cubic trends with random variances | 0.1497 | 0.0058 | (0.1383, 0.1610) | 0.4616 | 0.6571 | †52.2
Chinese origin:
Direct estimate | 0.0728 | 0.0201 | (0.0333, 0.1123) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0412 | 0.0087 | (0.0241, 0.0583) | -1.5686 | 0.4325 | 131.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.0412 | 0.0087 | (0.0241, 0.0583) | -1.5672 | 0.4330 | 130.9
MKF estimate: BMA up to cubic trends with random variances | 0.0383 | 0.0085 | (0.0217, 0.0549) | -1.7131 | 0.4203 | †137.9
Filipino origin:
Direct estimate | 0.0785 | 0.0204 | (0.0385, 0.1185) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0916 | 0.0106 | (0.0708, 0.1123) | 0.6412 | 0.5198 | 92.4
MKF estimate: Fully Bayesian linear trends with random variances | 0.0917 | 0.0106 | (0.0709, 0.1124) | 0.6460 | 0.5188 | 92.8
MKF estimate: BMA up to cubic trends with random variances | 0.0857 | 0.0093 | (0.0674, 0.1040) | 0.3538 | 0.4582 | †118.2
White:
Direct estimate | 0.1496 | 0.0035 | (0.1426, 0.1565) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1504 | 0.0031 | (0.1444, 0.1564) | 0.2295 | 0.8684 | 15.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.1504 | 0.0031 | (0.1443, 0.1564) | 0.2315 | 0.8721 | 14.7
MKF estimate: BMA up to cubic trends with random variances | 0.1503 | 0.0031 | (0.1443, 0.1564) | 0.2154 | 0.8722 | 14.7
Hispanic
Cuban origin:
Direct estimate | 0.0838 | 0.0223 | (0.0401, 0.1274) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0952 | 0.0105 | (0.0746, 0.1158) | 0.5150 | 0.4724 | 111.7
MKF estimate: Fully Bayesian linear trends with random variances | 0.0953 | 0.0105 | (0.0746, 0.1159) | 0.5168 | 0.4732 | 111.3
MKF estimate: BMA up to cubic trends with random variances | 0.0988 | 0.0095 | (0.0802, 0.1175) | 0.6773 | 0.4276 | †133.9
Mexican or Mexican-American origin:
Direct estimate | 0.0970 | 0.0096 | (0.0782, 0.1159) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0958 | 0.0059 | (0.0842, 0.1073) | -0.1299 | 0.6142 | 62.8
MKF estimate: Fully Bayesian linear trends with random variances | 0.0958 | 0.0059 | (0.0842, 0.1074) | -0.1279 | 0.6144 | 62.8
MKF estimate: BMA up to cubic trends with random variances | 0.0953 | 0.0059 | (0.0838, 0.1069) | -0.1724 | 0.6127 | †63.2
Puerto Rican origin:
Direct estimate | 0.1483 | 0.0227 | (0.1038, 0.1929) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1602 | 0.0099 | (0.1407, 0.1796) | 0.5214 | 0.4370 | 128.8
MKF estimate: Fully Bayesian linear trends with random variances | 0.1601 | 0.0099 | (0.1406, 0.1796) | 0.5192 | 0.4379 | 128.4
MKF estimate: BMA up to cubic trends with random variances | 0.1616 | 0.0091 | (0.1437, 0.1795) | 0.5834 | 0.4018 | †148.9
Other national origin:
Direct estimate | 0.0834 | 0.0122 | (0.0596, 0.1073) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0706 | 0.0069 | (0.0570, 0.0841) | -1.0607 | 0.5704 | 75.3
MKF estimate: Fully Bayesian linear trends with random variances | 0.0705 | 0.0069 | (0.0570, 0.0841) | -1.0629 | 0.5693 | 75.7
MKF estimate: BMA up to cubic trends with random variances | 0.0720 | 0.0068 | (0.0587, 0.0854) | -0.9393 | 0.5595 | †78.7
All other population subgroups^1^
Direct estimate | 0.1428 | 0.0143 | (0.1149, 0.1707) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.1464 | 0.0078 | (0.1311, 0.1616) | 0.2510 | 0.5465 | 83.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.1463 | 0.0078 | (0.1311, 0.1616) | 0.2476 | 0.5459 | 83.2
MKF estimate: BMA up to cubic trends with random variances | 0.1484 | 0.0075 | (0.1338, 0.1631) | 0.3959 | 0.5239 | †90.9

… Category not applicable.

† Indicates cases where the cubic Bayesian model averaging (BMA) trend model improves on the fully Bayesian model with linear trends.

1 All population subgroup categories, except the last, are single-race categories. The category All other population subgroups includes the Pacific Islander non-Hispanic only population, other Asian non-Hispanic only subgroups, and multiracial populations.

2 Direct estimates for 2018 are design-based, using only the 2018 National Health Interview Survey (NHIS). Modified Kalman filter (MKF) estimates for 2018 are model-based, using all 20 survey cycles from 1999 to 2018. Estimates based on the fully Bayesian linear trend model with fixed variances are as in the earlier version of the MKF procedure and macro. Estimates based on the fully Bayesian linear trend model with random variances use the enhanced MKF (eMKF) macro to account for the design-based variability in the sampling variances. Estimates based on cubic BMA also use the eMKF macro to account for the variability in the sampling variances and are weighted updated (posterior) averages over the following models: independent cubic, quadratic, and linear trends; common cubic, quadratic, and linear trends; and the intercepts-only trend model.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 The standardized difference between the MKF-based and direct estimates is calculated as: (MKF estimate minus direct estimate) divided by direct SE.

6 Relative RMSE (RRMSE) is calculated as the ratio: MKF RMSE divided by direct RMSE.

7 The percentage increase in equivalent sample size is calculated as 100 times (1 divided by RRMSE minus 1) and indicates the mean percentage increase in the equivalent sample size of 2018-only estimates due to the selected MKF model.

NOTES: All estimates shown are crude estimates, not adjusted for age. Current smokers have smoked at least 100 cigarettes in their lifetime and still currently smoke.

SOURCE: National Center for Health Statistics, National Health Interview Surveys, 2018.

Table VII Comparison of direct estimates to MKF estimates for the proportion of adults with kidney disease, by selected racial background and Hispanic ethnicity groups, from the fully Bayesian linear trend MKF model with fixed variances, the fully Bayesian linear trend MKF model with random variances, and the Bayesian model averaged cubic trend MKF model with random variances: United States, 2018

Population subgroup^1^ and estimation type^2^ | Estimate for 2018 | RMSE^3^ | 95% confidence interval^4^ | Standardized difference^5^ | Relative RMSE^6^ | Percent increase in equivalent sample size^7^
Non-Hispanic
American Indian and Alaska Native:
Direct estimate | 0.0249 | 0.0082 | (0.0087, 0.0411) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0238 | 0.0038 | (0.0163, 0.0312) | -0.1396 | 0.4592 | 117.8
MKF estimate: Fully Bayesian linear trends with random variances | 0.0238 | 0.0038 | (0.0164, 0.0312) | -0.1382 | 0.4583 | 118.2
MKF estimate: BMA up to cubic trends with random variances | 0.0213 | 0.0034 | (0.0147, 0.0279) | -0.4398 | 0.4076 | †145.3
Asian, Indian origin:
Direct estimate | 0.0056 | 0.0035 | (-0.0011, 0.0124) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0029 | 0.0017 | (-0.0004, 0.0063) | -0.7907 | 0.4951 | 102.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.0029 | 0.0017 | (-0.0005, 0.0063) | -0.7949 | 0.4959 | 101.7
MKF estimate: BMA up to cubic trends with random variances | 0.0035 | 0.0021 | (-0.0006, 0.0077) | -0.6114 | 0.6116 | 63.5
Black:
Direct estimate | 0.0301 | 0.0032 | (0.0238, 0.0364) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0264 | 0.0016 | (0.0233, 0.0295) | -1.1500 | 0.4874 | 105.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.0264 | 0.0016 | (0.0233, 0.0295) | -1.1518 | 0.4860 | 105.8
MKF estimate: BMA up to cubic trends with random variances | 0.0253 | 0.0019 | (0.0215, 0.0291) | -1.4958 | 0.5972 | 67.4
Chinese origin:
Direct estimate | *0.0274 | 0.0132 | (0.0016, 0.0532) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0121 | 0.0028 | (0.0066, 0.0176) | -1.1613 | 0.2138 | 367.7
MKF estimate: Fully Bayesian linear trends with random variances | 0.0121 | 0.0028 | (0.0066, 0.0176) | -1.1616 | 0.2134 | 368.6
MKF estimate: BMA up to cubic trends with random variances | 0.0092 | 0.0030 | (0.0033, 0.0151) | -1.3826 | 0.2277 | 339.2
Filipino origin:
Direct estimate | *0.0323 | 0.0145 | (0.0040, 0.0607) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0074 | 0.0021 | (0.0033, 0.0114) | -1.7252 | 0.1424 | 602.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.0074 | 0.0021 | (0.0033, 0.0114) | -1.7250 | 0.1418 | 605.2
MKF estimate: BMA up to cubic trends with random variances | 0.0054 | 0.0022 | (0.0011, 0.0098) | -1.8601 | 0.1533 | 552.3
White:
Direct estimate | 0.0241 | 0.0014 | (0.0213, 0.0269) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0222 | 0.0010 | (0.0202, 0.0243) | -1.3224 | 0.7373 | 35.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.0222 | 0.0011 | (0.0201, 0.0243) | -1.3353 | 0.7449 | 34.2
MKF estimate: BMA up to cubic trends with random variances | 0.0226 | 0.0012 | (0.0203, 0.0249) | -1.0438 | 0.8179 | 22.3
Hispanic
Cuban origin:
Direct estimate | *0.0253 | 0.0103 | (0.0051, 0.0455) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0111 | 0.0032 | (0.0048, 0.0174) | -1.3732 | 0.3127 | 219.8
MKF estimate: Fully Bayesian linear trends with random variances | 0.0111 | 0.0032 | (0.0048, 0.0175) | -1.3730 | 0.3136 | 218.9
MKF estimate: BMA up to cubic trends with random variances | 0.0161 | 0.0031 | (0.0100, 0.0222) | -0.8935 | 0.3015 | †231.7
Mexican or Mexican-American origin:
Direct estimate | 0.0200 | 0.0043 | (0.0115, 0.0285) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0191 | 0.0017 | (0.0157, 0.0224) | -0.2180 | 0.3981 | 151.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.0191 | 0.0017 | (0.0157, 0.0224) | -0.2200 | 0.3972 | 151.8
MKF estimate: BMA up to cubic trends with random variances | 0.0190 | 0.0021 | (0.0148, 0.0232) | -0.2354 | 0.4944 | 102.3
Puerto Rican origin:
Direct estimate | 0.0094 | 0.0041 | (0.0013, 0.0175) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0151 | 0.0024 | (0.0104, 0.0198) | 1.3833 | 0.5794 | 72.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.0151 | 0.0024 | (0.0104, 0.0198) | 1.3809 | 0.5794 | 72.6
MKF estimate: BMA up to cubic trends with random variances | 0.0153 | 0.0024 | (0.0105, 0.0201) | 1.4305 | 0.5936 | 68.5
Other national origin:
Direct estimate | 0.0178 | 0.0044 | (0.0092, 0.0263) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0134 | 0.0020 | (0.0095, 0.0172) | -1.0098 | 0.4489 | 122.8
MKF estimate: Fully Bayesian linear trends with random variances | 0.0133 | 0.0019 | (0.0095, 0.0172) | -1.0117 | 0.4473 | 123.6
MKF estimate: BMA up to cubic trends with random variances | 0.0151 | 0.0023 | (0.0106, 0.0195) | -0.6180 | 0.5221 | 91.5
All other population subgroups^1^
Direct estimate | 0.0307 | 0.0064 | (0.0181, 0.0433) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0193 | 0.0022 | (0.0150, 0.0236) | -1.7713 | 0.3426 | 191.9
MKF estimate: Fully Bayesian linear trends with random variances | 0.0193 | 0.0022 | (0.0149, 0.0236) | -1.7733 | 0.3432 | 191.4
MKF estimate: BMA up to cubic trends with random variances | 0.0190 | 0.0025 | (0.0142, 0.0239) | -1.8093 | 0.3835 | 160.8

… Category not applicable.

† Indicates cases where the cubic Bayesian model averaging (BMA) trend model improves on the fully Bayesian model with linear trends.

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 All population subgroup categories, except the last, are single-race categories. The category All other population subgroups includes the Pacific Islander non-Hispanic only population, other Asian non-Hispanic only subgroups, and multiracial populations.

2 Direct estimates for 2018 are design-based, using only the 2018 National Health Interview Survey (NHIS). Modified Kalman filter (MKF) estimates for 2018 are model-based, using all 20 survey cycles from 1999 to 2018. Estimates based on the fully Bayesian linear trend model with fixed variances are as in the earlier version of the MKF procedure and macro. Estimates based on the fully Bayesian linear trend model with random variances use the enhanced MKF (eMKF) macro to account for the design-based variability in the sampling variances. Estimates based on cubic BMA also use the eMKF macro to account for the variability in the sampling variances and are weighted updated (posterior) averages over the following models: independent cubic, quadratic, and linear trends; common cubic, quadratic, and linear trends; and the intercepts-only trend model.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 The standardized difference between the MKF-based and direct estimates is calculated as: (MKF estimate minus direct estimate) divided by direct SE.

6 Relative RMSE (RRMSE) is calculated as the ratio: MKF RMSE divided by direct RMSE.

7 The percentage increase in equivalent sample size is calculated as 100 times (1 divided by RRMSE minus 1) and indicates the mean percentage increase in the equivalent sample size of 2018-only estimates due to the selected MKF model.

NOTES: All estimates shown are crude estimates, not adjusted for age. Respondents were asked if they had been told in the last 12 months by a doctor or other health professional that they had weak or failing kidneys (excluding kidney stones, bladder infections, or incontinence).

SOURCE: National Center for Health Statistics, National Health Interview Surveys, 2018.

Table VIII Comparison of direct estimates to MKF estimates for the proportion of adults who had a stroke, by selected racial background and Hispanic ethnicity groups, from the fully Bayesian linear trend MKF model with fixed variances, the fully Bayesian linear trend MKF model with random variances, and the Bayesian model averaged cubic trend MKF model with random variances: United States, 2018

Population subgroup^1^ and estimation type^2^ | Estimate for 2018 | RMSE^3^ | 95% confidence interval^4^ | Standardized difference^5^ | Relative RMSE^6^ | Percent increase in equivalent sample size^7^
Non-Hispanic
American Indian and Alaska Native:
Direct estimate | 0.0235 | 0.0095 | (0.0049, 0.0421) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0247 | 0.0037 | (0.0175, 0.0319) | 0.1288 | 0.3865 | 158.7
MKF estimate: Fully Bayesian linear trends with random variances | 0.0248 | 0.0036 | (0.0176, 0.0319) | 0.1313 | 0.3844 | 160.1
MKF estimate: BMA up to cubic trends with random variances | 0.0252 | 0.0035 | (0.0184, 0.0320) | 0.1788 | 0.3646 | †174.3
Asian, Indian origin:
Direct estimate | 0.0084 | 0.0073 | (-0.0059, 0.0228) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0078 | 0.0028 | (0.0024, 0.0132) | -0.0896 | 0.3772 | 165.1
MKF estimate: Fully Bayesian linear trends with random variances | 0.0078 | 0.0028 | (0.0024, 0.0132) | -0.0847 | 0.3770 | 165.3
MKF estimate: BMA up to cubic trends with random variances | 0.0082 | 0.0028 | (0.0027, 0.0138) | -0.0267 | 0.3875 | 158.1
Black:
Direct estimate | 0.0404 | 0.0037 | (0.0330, 0.0477) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0397 | 0.0023 | (0.0352, 0.0441) | -0.1907 | 0.6090 | 64.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.0396 | 0.0023 | (0.0352, 0.0441) | -0.1997 | 0.6062 | 65.0
MKF estimate: BMA up to cubic trends with random variances | 0.0388 | 0.0022 | (0.0345, 0.0431) | -0.4144 | 0.5895 | †69.6
Chinese origin:
Direct estimate | 0.0136 | 0.0094 | (-0.0048, 0.0320) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0096 | 0.0029 | (0.0040, 0.0153) | -0.4187 | 0.3091 | 223.5
MKF estimate: Fully Bayesian linear trends with random variances | 0.0097 | 0.0029 | (0.0040, 0.0154) | -0.4141 | 0.3087 | 223.9
MKF estimate: BMA up to cubic trends with random variances | 0.0108 | 0.0028 | (0.0052, 0.0163) | -0.2990 | 0.3026 | †230.5
Filipino origin:
Direct estimate | 0.0426 | 0.0126 | (0.0180, 0.0672) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0174 | 0.0033 | (0.0109, 0.0239) | -2.0071 | 0.2632 | 279.9
MKF estimate: Fully Bayesian linear trends with random variances | 0.0174 | 0.0033 | (0.0109, 0.0238) | -2.0086 | 0.2613 | 282.7
MKF estimate: BMA up to cubic trends with random variances | 0.0174 | 0.0032 | (0.0112, 0.0236) | -2.0046 | 0.2511 | †298.2
White:
Direct estimate | 0.0334 | 0.0016 | (0.0302, 0.0365) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0329 | 0.0013 | (0.0303, 0.0355) | -0.3009 | 0.8335 | 20.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.0329 | 0.0013 | (0.0302, 0.0355) | -0.2987 | 0.8361 | 19.6
MKF estimate: BMA up to cubic trends with random variances | 0.0329 | 0.0014 | (0.0303, 0.0356) | -0.2837 | 0.8380 | 19.3
Hispanic
Cuban origin:
Direct estimate | *0.0253 | 0.0117 | (0.0024, 0.0482) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0179 | 0.0034 | (0.0112, 0.0245) | -0.6337 | 0.2897 | 245.2
MKF estimate: Fully Bayesian linear trends with random variances | 0.0179 | 0.0034 | (0.0113, 0.0245) | -0.6294 | 0.2891 | 245.9
MKF estimate: BMA up to cubic trends with random variances | 0.0190 | 0.0032 | (0.0127, 0.0254) | -0.5351 | 0.2764 | †261.8
Mexican or Mexican-American origin:
Direct estimate | 0.0181 | 0.0032 | (0.0119, 0.0243) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0195 | 0.0021 | (0.0154, 0.0235) | 0.4164 | 0.6510 | 53.6
MKF estimate: Fully Bayesian linear trends with random variances | 0.0195 | 0.0021 | (0.0154, 0.0235) | 0.4154 | 0.6498 | 53.9
MKF estimate: BMA up to cubic trends with random variances | 0.0192 | 0.0020 | (0.0152, 0.0233) | 0.3479 | 0.6485 | †54.2
Puerto Rican origin:
Direct estimate | 0.0212 | 0.0081 | (0.0053, 0.0371) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0275 | 0.0033 | (0.0211, 0.0339) | 0.7805 | 0.4010 | 149.4
MKF estimate: Fully Bayesian linear trends with random variances | 0.0275 | 0.0032 | (0.0212, 0.0339) | 0.7835 | 0.3992 | 150.5
MKF estimate: BMA up to cubic trends with random variances | 0.0280 | 0.0031 | (0.0219, 0.0342) | 0.8427 | 0.3874 | †158.1
Other national origin:
Direct estimate | 0.0232 | 0.0068 | (0.0098, 0.0365) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0177 | 0.0027 | (0.0125, 0.0230) | -0.8013 | 0.3938 | 153.9
MKF estimate: Fully Bayesian linear trends with random variances | 0.0177 | 0.0026 | (0.0125, 0.0229) | -0.8036 | 0.3893 | 156.9
MKF estimate: BMA up to cubic trends with random variances | 0.0175 | 0.0026 | (0.0124, 0.0226) | -0.8333 | 0.3850 | †159.7
All other population subgroups^1^
Direct estimate | 0.0312 | 0.0060 | (0.0194, 0.0429) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 0.0280 | 0.0028 | (0.0226, 0.0334) | -0.5307 | 0.4608 | 117.0
MKF estimate: Fully Bayesian linear trends with random variances | 0.0280 | 0.0027 | (0.0226, 0.0333) | -0.5330 | 0.4583 | 118.2
MKF estimate: BMA up to cubic trends with random variances | 0.0277 | 0.0027 | (0.0225, 0.0329) | -0.5776 | 0.4467 | †123.9

… Category not applicable.

† Indicates cases where the cubic Bayesian model averaging (BMA) trend model improves on the fully Bayesian model with linear trends.

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 All population subgroup categories, except the last, are single-race categories. The category All other population subgroups includes the Pacific Islander non-Hispanic only population, other Asian non-Hispanic only subgroups, and multiracial populations.

2 Direct estimates for 2018 are design-based, using only the 2018 National Health Interview Survey (NHIS). Modified Kalman filter (MKF) estimates for 2018 are model-based, using all 20 survey cycles from 1999 to 2018. Estimates based on the fully Bayesian linear trend model with fixed variances are as in the earlier version of the MKF procedure and macro. Estimates based on the fully Bayesian linear trend model with random variances use the enhanced MKF (eMKF) macro to account for the design-based variability in the sampling variances. Estimates based on cubic BMA also use the eMKF macro to account for the variability in the sampling variances and are weighted updated (posterior) averages over the following models: independent cubic, quadratic, and linear trends; common cubic, quadratic, and linear trends; and the intercepts-only trend model.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 The standardized difference between the MKF-based and direct estimates is calculated as: (MKF estimate minus direct estimate) divided by direct SE.

6 Relative RMSE (RRMSE) is calculated as the ratio: MKF RMSE divided by direct RMSE.

7 The percentage increase in equivalent sample size is calculated as 100 times (1 divided by RRMSE minus 1) and indicates the mean percentage increase in the equivalent sample size of 2018-only estimates due to the selected MKF model.

NOTES: All estimates shown are crude estimates, not adjusted for age. Respondents were asked if they had ever been told by a doctor or other health professional that they had a stroke.

SOURCE: National Center for Health Statistics, National Health Interview Surveys, 2018.

Table IX Comparison of direct estimates to MKF estimates for adult mean body mass index, by selected racial background and Hispanic ethnicity groups, from the fully Bayesian linear trend MKF model with fixed variances, the fully Bayesian linear trend MKF model with random variances, and the Bayesian model averaged cubic trend MKF model with random variances: United States, 2018

Population subgroup^1^ and estimation type^2^ | Estimate for 2018 | RMSE^3^ | 95% confidence interval^4^ | Standardized difference^5^ | Relative RMSE^6^ | Percent increase in equivalent sample size^7^
Non-Hispanic
American Indian and Alaska Native:
Direct estimate | 31.6813 | 1.0691 | (29.5858, 33.7768) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 30.0703 | 0.2632 | (29.5544, 30.5862) | -1.5069 | 0.2462 | 306.2
MKF estimate: Fully Bayesian linear trends with random variances | 30.0705 | 0.2631 | (29.5549, 30.5862) | -1.5066 | 0.2461 | 306.3
MKF estimate: BMA up to cubic trends with random variances | 30.0203 | 0.2404 | (29.5490, 30.4915) | -1.5536 | 0.2249 | †344.6
Asian, Indian origin:
Direct estimate | 25.6040 | 0.2287 | (25.1557, 26.0522) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 25.5209 | 0.1428 | (25.2410, 25.8008) | -0.3629 | 0.6244 | 60.2
MKF estimate: Fully Bayesian linear trends with random variances | 25.5214 | 0.1436 | (25.2399, 25.8029) | -0.3608 | 0.6279 | 59.3
MKF estimate: BMA up to cubic trends with random variances | 25.5177 | 0.1420 | (25.2393, 25.7960) | -0.3772 | 0.6209 | †61.1
Black:
Direct estimate | 29.4951 | 0.1780 | (29.1462, 29.8440) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 29.6247 | 0.1203 | (29.3889, 29.8605) | 0.7280 | 0.6758 | 48.0
MKF estimate: Fully Bayesian linear trends with random variances | 29.6240 | 0.1203 | (29.3882, 29.8597) | 0.7241 | 0.6757 | 48.0
MKF estimate: BMA up to cubic trends with random variances | 29.6060 | 0.1196 | (29.3716, 29.8403) | 0.6228 | 0.6716 | †48.9
Chinese origin:
Direct estimate | 23.2748 | 0.2832 | (22.7198, 23.8298) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 23.3194 | 0.1597 | (23.0064, 23.6323) | 0.1574 | 0.5639 | 77.3
MKF estimate: Fully Bayesian linear trends with random variances | 23.3204 | 0.1600 | (23.0068, 23.6339) | 0.1609 | 0.5650 | 77.0
MKF estimate: BMA up to cubic trends with random variances | 23.3935 | 0.1575 | (23.0849, 23.7021) | 0.4191 | 0.5561 | †79.8
Filipino origin:
Direct estimate | 26.1265 | 0.3642 | (25.4128, 26.8402) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 26.1603 | 0.1784 | (25.8107, 26.5099) | 0.0928 | 0.4898 | 104.2
MKF estimate: Fully Bayesian linear trends with random variances | 26.1612 | 0.1786 | (25.8112, 26.5112) | 0.0953 | 0.4904 | 103.9
MKF estimate: BMA up to cubic trends with random variances | 26.1382 | 0.1736 | (25.7980, 26.4784) | 0.0321 | 0.4766 | †109.8
White:
Direct estimate | 27.9682 | 0.0690 | (27.8330, 28.1033) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 27.9760 | 0.0605 | (27.8575, 28.0946) | 0.1141 | 0.8770 | 14.0
MKF estimate: Fully Bayesian linear trends with random variances | 27.9762 | 0.0608 | (27.8571, 28.0954) | 0.1170 | 0.8813 | 13.5
MKF estimate: BMA up to cubic trends with random variances | 27.9716 | 0.0610 | (27.8520, 28.0912) | 0.0492 | 0.8848 | 13.0
Hispanic
Cuban origin:
Direct estimate | 28.2266 | 0.6024 | (27.0460, 29.4073) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 27.6557 | 0.2065 | (27.2509, 28.0605) | -0.9478 | 0.3429 | 191.6
MKF estimate: Fully Bayesian linear trends with random variances | 27.6583 | 0.2079 | (27.2508, 28.0657) | -0.9436 | 0.3451 | 189.8
MKF estimate: BMA up to cubic trends with random variances | 27.7055 | 0.1984 | (27.3166, 28.0943) | -0.8652 | 0.3293 | †203.7
Mexican or Mexican-American origin:
Direct estimate | 28.9188 | 0.1978 | (28.5312, 29.3065) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 28.9621 | 0.1244 | (28.7182, 29.2059) | 0.2186 | 0.6290 | 59.0
MKF estimate: Fully Bayesian linear trends with random variances | 28.9622 | 0.1249 | (28.7174, 29.2070) | 0.2192 | 0.6314 | 58.4
MKF estimate: BMA up to cubic trends with random variances | 28.9487 | 0.1251 | (28.7036, 29.1938) | 0.1510 | 0.6322 | 58.2
Puerto Rican origin:
Direct estimate | 29.5216 | 0.4959 | (28.5497, 30.4935) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 29.0040 | 0.1866 | (28.6382, 29.3698) | -1.0439 | 0.3764 | 165.7
MKF estimate: Fully Bayesian linear trends with random variances | 29.0038 | 0.1870 | (28.6373, 29.3703) | -1.0442 | 0.3771 | 165.2
MKF estimate: BMA up to cubic trends with random variances | 28.9811 | 0.1801 | (28.6280, 29.3342) | -1.0900 | 0.3633 | †175.3
Other national origin:
Direct estimate | 28.1578 | 0.2812 | (27.6068, 28.7089) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 27.9823 | 0.1541 | (27.6802, 28.2843) | -0.6245 | 0.5480 | 82.5
MKF estimate: Fully Bayesian linear trends with random variances | 27.9826 | 0.1536 | (27.6816, 28.2837) | -0.6232 | 0.5463 | 83.0
MKF estimate: BMA up to cubic trends with random variances | 27.9579 | 0.1536 | (27.6569, 28.2589) | -0.7111 | 0.5462 | †83.1
All other population subgroups^1^
Direct estimate | 26.9938 | 0.3298 | (26.3474, 27.6401) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 26.5033 | 0.1622 | (26.1854, 26.8211) | -1.4875 | 0.4917 | 103.4
MKF estimate: Fully Bayesian linear trends with random variances | 26.5045 | 0.1623 | (26.1864, 26.8225) | -1.4839 | 0.4921 | 103.2
MKF estimate: BMA up to cubic trends with random variances | 26.5200 | 0.1601 | (26.2062, 26.8338) | -1.4367 | 0.4855 | †106.0

… Category not applicable.

† Indicates cases where the cubic Bayesian model averaging (BMA) trend model improves on the fully Bayesian model with linear trends.

1 All population subgroup categories, except the last, are single-race categories. The category All other population subgroups includes the Pacific Islander non-Hispanic only population, other Asian non-Hispanic only subgroups, and multiracial populations.

2 Direct estimates for 2018 are design-based, using only the 2018 National Health Interview Survey (NHIS). Modified Kalman filter (MKF) estimates for 2018 are model-based, using all 20 survey cycles from 1999 to 2018. Estimates based on the fully Bayesian linear trend model with fixed variances are as in the earlier version of the MKF procedure and macro. Estimates based on the fully Bayesian linear trend model with random variances use the enhanced MKF (eMKF) macro to account for the design-based variability in the sampling variances. Estimates based on cubic BMA also use the eMKF macro to account for the variability in the sampling variances and are weighted updated (posterior) averages over the following models: independent cubic, quadratic, and linear trends; common cubic, quadratic, and linear trends; and the intercepts-only trend model.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 The standardized difference between the MKF-based and direct estimates is calculated as: (MKF estimate minus direct estimate) divided by direct SE.

6 Relative RMSE (RRMSE) is calculated as the ratio: MKF RMSE divided by direct RMSE.

7 The percentage increase in equivalent sample size is calculated as 100 times (1 divided by RRMSE minus 1) and indicates the mean percentage increase in the equivalent sample size of 2018-only estimates due to the selected MKF model.

NOTES: All estimates shown are crude estimates, not adjusted for age. Body mass index (BMI) is calculated from information that respondents supplied in response to survey questions regarding height and weight and defined as BMI equals weight (kilograms) divided by height (meters)^2^. Note that self-reported height and weight may differ from actual measurements.

SOURCE: National Center for Health Statistics, National Health Interview Surveys, 2018.

Table X Comparison of direct estimates to MKF estimates for mean number of bed days per adult, by selected racial background and Hispanic ethnicity groups, from the fully Bayesian linear trend MKF model with fixed variances, the fully Bayesian linear trend MKF model with random variances, and the Bayesian model averaged cubic trend MKF model with random variances: United States, 2018

Population subgroup^1^ and estimation type^2^ | Estimate for 2018 | RMSE^3^ | 95% confidence interval^4^ | Standardized difference^5^ | Relative RMSE^6^ | Percent increase in equivalent sample size^7^
Non-Hispanic
American Indian and Alaska Native:
Direct estimate | *12.1813 | 4.8082 | (2.7572, 21.6054) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 5.0871 | 0.6905 | (3.7337, 6.4404) | -1.4755 | 0.1436 | 596.4
MKF estimate: Fully Bayesian linear trends with random variances | 5.0930 | 0.6923 | (3.7360, 6.4500) | -1.4742 | 0.1440 | 594.4
MKF estimate: BMA up to cubic trends with random variances | 5.0184 | 0.6864 | (3.6731, 6.3638) | -1.4897 | 0.1428 | †600.3
Asian, Indian origin:
Direct estimate | 1.8895 | 0.4846 | (0.9396, 2.8393) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 1.6249 | 0.3560 | (0.9271, 2.3226) | -0.5460 | 0.7346 | 36.1
MKF estimate: Fully Bayesian linear trends with random variances | 1.6242 | 0.3570 | (0.9245, 2.3239) | -0.5473 | 0.7366 | 35.8
MKF estimate: BMA up to cubic trends with random variances | 1.5342 | 0.3536 | (0.8411, 2.2273) | -0.7331 | 0.7297 | †37.0
Black:
Direct estimate | 5.1945 | 0.5656 | (4.0860, 6.3031) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 5.4914 | 0.3914 | (4.7243, 6.2585) | 0.5249 | 0.6920 | 44.5
MKF estimate: Fully Bayesian linear trends with random variances | 5.4899 | 0.3906 | (4.7243, 6.2556) | 0.5222 | 0.6907 | 44.8
MKF estimate: BMA up to cubic trends with random variances | 5.4234 | 0.3901 | (4.6588, 6.1881) | 0.4047 | 0.6898 | †45.0
Chinese origin:
Direct estimate | 1.1292 | 0.2356 | (0.6674, 1.5910) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 1.2105 | 0.2191 | (0.7811, 1.6399) | 0.3451 | 0.9297 | 7.6
MKF estimate: Fully Bayesian linear trends with random variances | 1.2105 | 0.2191 | (0.7810, 1.6400) | 0.3452 | 0.9300 | 7.5
MKF estimate: BMA up to cubic trends with random variances | 1.1934 | 0.2180 | (0.7662, 1.6207) | 0.2726 | 0.9252 | †8.1
Filipino origin:
Direct estimate | *6.8171 | 2.8961 | (1.1407, 12.4935) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 2.8299 | 0.5866 | (1.6801, 3.9796) | -1.3768 | 0.2025 | 393.8
MKF estimate: Fully Bayesian linear trends with random variances | 2.8338 | 0.5850 | (1.6873, 3.9803) | -1.3754 | 0.2020 | 395.0
MKF estimate: BMA up to cubic trends with random variances | 2.5703 | 0.5721 | (1.4489, 3.6917) | -1.4664 | 0.1976 | †406.1
White:
Direct estimate | 5.4587 | 0.2608 | (4.9475, 5.9699) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 5.3853 | 0.2300 | (4.9346, 5.8360) | -0.2813 | 0.8816 | 13.4
MKF estimate: Fully Bayesian linear trends with random variances | 5.3864 | 0.2306 | (4.9345, 5.8383) | -0.2770 | 0.8839 | 13.1
MKF estimate: BMA up to cubic trends with random variances | 5.3466 | 0.2318 | (4.8924, 5.8009) | -0.4296 | 0.8886 | 12.5
Hispanic
Cuban origin:
Direct estimate | 3.5083 | 1.2649 | (1.0290, 5.9876) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 2.3797 | 0.5273 | (1.3463, 3.4132) | -0.8922 | 0.4168 | 139.9
MKF estimate: Fully Bayesian linear trends with random variances | 2.3762 | 0.5283 | (1.3407, 3.4118) | -0.8950 | 0.4177 | 139.4
MKF estimate: BMA up to cubic trends with random variances | 2.3193 | 0.5077 | (1.3242, 3.3143) | -0.9400 | 0.4013 | †149.2
Mexican or Mexican-American origin:
Direct estimate | 3.9632 | 0.7140 | (2.5637, 5.3627) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 3.6179 | 0.4321 | (2.7710, 4.4649) | -0.4835 | 0.6052 | 65.2
MKF estimate: Fully Bayesian linear trends with random variances | 3.6209 | 0.4316 | (2.7751, 4.4668) | -0.4793 | 0.6044 | 65.5
MKF estimate: BMA up to cubic trends with random variances | 3.4873 | 0.4344 | (2.6359, 4.3386) | -0.6665 | 0.6083 | 64.4
Puerto Rican origin:
Direct estimate | 6.2665 | 1.6123 | (3.1065, 9.4266) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 5.9941 | 0.5924 | (4.8331, 7.1551) | -0.1690 | 0.3674 | 172.2
MKF estimate: Fully Bayesian linear trends with random variances | 5.9923 | 0.5930 | (4.8301, 7.1546) | -0.1701 | 0.3678 | 171.9
MKF estimate: BMA up to cubic trends with random variances | 5.8731 | 0.5856 | (4.7253, 7.0209) | -0.2440 | 0.3632 | †175.3
Other national origin:
Direct estimate | 4.7786 | 1.2255 | (2.3765, 7.1806) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 3.3820 | 0.5214 | (2.3600, 4.4039) | -1.1396 | 0.4255 | 135.0
MKF estimate: Fully Bayesian linear trends with random variances | 3.3826 | 0.5204 | (2.3626, 4.4025) | -1.1391 | 0.4246 | 135.5
MKF estimate: BMA up to cubic trends with random variances | 3.3210 | 0.5198 | (2.3021, 4.3399) | -1.1894 | 0.4242 | †135.7
All other population subgroups^1^
Direct estimate | 7.0979 | 1.5021 | (4.1536, 10.0421) | … | … | …
MKF estimate: Fully Bayesian linear trends with fixed variances | 4.8836 | 0.5680 | (3.7703, 5.9969) | -1.4740 | 0.3781 | 164.5
MKF estimate: Fully Bayesian linear trends with random variances | 4.8844 | 0.5696 | (3.7680, 6.0008) | -1.4735 | 0.3792 | 163.7
MKF estimate: BMA up to cubic trends with random variances | 4.8122 | 0.5622 | (3.7103, 5.9141) | -1.5216 | 0.3743 | †167.2

* Estimate does not meet National Center for Health Statistics standards of reliability.

… Category not applicable.

† Indicates cases where the cubic Bayesian model averaging (BMA) trend model improves on the fully Bayesian model with linear trends.

1 All population subgroup categories, except the last, are single-race categories. The category All other population subgroups includes the Pacific Islander non-Hispanic only population, other Asian non-Hispanic only subgroups, and multiracial populations.

2 Direct estimates for 2018 are design-based, using only the 2018 National Health Interview Survey (NHIS). Modified Kalman filter (MKF) estimates for 2018 are model-based, using all 20 survey cycles from 1999 to 2018. Estimates based on the fully Bayesian linear trend model with fixed variances are as in the earlier version of the MKF procedure and macro. Estimates based on the fully Bayesian linear trend model with random variances use the enhanced MKF (eMKF) macro to account for the design-based variability in the sampling variances. Estimates based on cubic BMA also use the eMKF macro to account for the variability in the sampling variances and are weighted updated (posterior) averages over the following models: independent cubic, quadratic, and linear trends; common cubic, quadratic, and linear trends; and the intercepts-only trend model.

3 Root mean squared error (RMSE) is defined as the square root of the sum of the squared deviations from the mean, which may or may not be the population quantity of interest. For a direct estimate, which is assumed unbiased, RMSE is the estimate's (design-based) standard error (SE). For a model-based estimate, which may be biased, RMSE can be written as the sum of the squared SE and the squared bias, highlighting the bias–variance trade-off.

4 Wald 95% confidence interval is calculated as: estimate plus or minus 1.96 times RMSE.

5 The standardized difference between the MKF-based and direct estimates is calculated as: (MKF estimate minus direct estimate) divided by direct SE.

6 Relative RMSE (RRMSE) is calculated as the ratio: MKF RMSE divided by direct RMSE.

7 The percentage increase in equivalent sample size is calculated as 100 times (1 divided by RRMSE minus 1) and indicates the mean percentage increase in the equivalent sample size of 2018-only estimates due to the selected MKF model.

NOTES: All estimates shown are crude estimates, not adjusted for age. Respondents were asked, ‘‘During the past 12 months, about how many days did illness or injury keep you in the bed more than half of the day (include days while an overnight patient in a hospital)?"

SOURCE: National Center for Health Statistics, National Health Interview Surveys, 2018.