# Front Matter

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Research and Methodology

Jennifer D. Parker, Ph.D., Director

John R. Pleis, Ph.D., Associate Director for Science

For answers to questions about this report or for a list of reports published in these series, contact:

Information Dissemination Staff

National Center for Health Statistics

Centers for Disease Control and Prevention

3311 Toledo Road, Room 4551, MS P08

Hyattsville, MD 20782

Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/email-updates.htm.

Series 2, No. 208

CS350411