# References

1 Institute of Medicine (US) Committee on Understanding and Eliminating Racial and Ethnic Disparities in Health Care; Smedley BD, Stith AY, Nelson AR, editors. Unequal treatment: Confronting racial and ethnic disparities in health care. Washington, DC: National Academies Press. 2003.
2 U.S. Department of Health and Human Services, Office of Disease Prevention and Health Promotion. Healthy People 2020: Social determinants of health. 2010. Available from: https://wayback.archive-it.org/5774/20220413203948/https://www.healthypeople.gov/2020/topics-objectives/topic/social-determinants-of-health.
3 Turner A. The business case for racial equity: A strategy for growth. W.K. Kellogg Foundation, Publication #590. 2018.
4 Colby SL, Ortman JM. Projections of the size and composition of the U.S. population: 2014 to 2060. U.S. Census Bureau, Current Population Reports. P25–1143. 2015.
5 U.S. Department of Health and HumanServices, Office of Minority Health. National standards for culturally and linguistically appropriate services in health and health care: A blueprint for advancing and sustaining CLAS policy and practice. 2013. Available from: https://thinkculturalhealth.hhs.gov/assets/pdfs/EnhancedCLASStandardsBlueprint.pdf.
6 U.S. Department of Health and Human Services. HHS action plan to reduce racial and ethnic health disparities: Implementation progress report 2011–2014. 2015. Available from: https://aspe.hhs.gov/sites/default/files/private/pdf/206166/DisparitiesActionPlan.pdf.
7 U.S. Department of Health and Human Services, Office of Minority Health. National standards for culturally and linguistically appropriate services in health care: Final report. 2001. Available from: https://www.searac.org/wp-content/uploads/2018/04/National-Standards-Report.pdf.
8 Heckler MM. Report of the Secretary’s Task Force on Black & Minority Health. Washington, DC: U.S. Department of Health and Human Services. 1985. Available from: https://collections.nlm.nih.gov/catalog/nlm:nlmuid-8602912-mvset.
9 U.S. Department of Health and Human Services, Office of Minority Health. About the Office of Minority Health. Available from: https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=1&lvlid=1.
10 Office of Minority Health. National standards on culturally and linguistically appropriate services (CLAS) in health care. Fed Regist 65(247):80865–79. 2000.
11 Office of Minority Health. National standards on culturally and linguistically appropriate services (CLAS) in health care. Fed Regist 78(185):58539–43. 2013.
12 Betancourt JR. Improving quality and achieving equity: The role of cultural competence in reducing racial and ethnic disparities in health care. The Commonwealth Fund. 2006. Available from: https://www.commonwealthfund.org/sites/default/files/documents/___media_files_publications_fund_report_2006_oct_improving_quality_and_achieving_equity__the_role_of_cultural_competence_in_reducing_racial_and_ethni_betancourt_improvingqualityachievingequity_961_pdf.pdf.
13 Lie DA, Lee-Rey E, Gomez A, Bereknyei S, Braddock CH 3rd. Does cultural competency training of health professionals improve patient outcomes? A systematic review and proposed algorithm for future research. J Gen Intern Med 26(3):317–25. 2011.20953728
14 National Center for Health Statistics. 2016 NAMCS micro-data file documentation. 2019. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/NAMCS/doc2016.pdf.
15 National Center for Health Statistics. 2016 National Ambulatory Medical Care Survey supplement on culturally and linguistically appropriate services for office-based physicians (National CLAS Physician Survey) public use file documentation. 2018. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/NAMCS/doc2016_clas.pdf.
16 Mason JL. Cultural competence self-assessment questionnaire: A manual for users. 1995.
17 Godkin MA, Savageau JA. The effect of a global multiculturalism track on cultural competence of preclinical medical students. Fam Med 33(3):178–86. 2001.11302510
18 Association of American Medical Colleges. Tool for assessing cultural competence training (TACCT). 2016. Available from: https://www.aamc.org/system/files/c/2/54344-tacct_pdf.pdf.
19 Schim SM, Doorenbos AZ, Miller J, Benkert R. Development of a cultural competence assessment instrument. J Nurs Meas 11(1):29–40. 2003.15132010
20 The National Center for Cultural Competence. Report of significant accomplishments for the National Center for Cultural Competence. Georgetown University Center for Child and Human Development. 2011.
21 Godkin M, Savageau J. The effect of medical students’ international experiences on attitudes toward serving underserved multicultural populations. Fam Med 35(4):273–8. 2003.12729313
22 Gozu A, Beach MC, Price EG, Gary TL, Robinson K, Palacio A, et al. Self-administered instruments to measure cultural competence of health professionals: A systematic review. Teach Learn Med 19(2):180–90. 2007.17564547
23 Salvaggio M, Dunston S. 2016 National Ambulatory Medical Care Survey (NAMCS) culturally and linguistically appropriate services (CLAS) supplement. 2016. Available from: https://wwwn.cdc.gov/QBank/Report.aspx?1156.
24 Tourangeau R, Rips LJ, Rasinski K. The psychology of survey response. New York, NY: Cambridge University Press. 2000.
25 Willis GB. Cognitive interviewing: A tool for improving questionnaire design. Thousand Oaks, CA: Sage Publications, Inc. 2005.
26 Miller K, Wilson S, Chepp V, Padilla JL. Cognitive interviewing methodology. Hoboken, NJ: Wiley & Sons, Inc. 2014.
27 Bradburn N, Sudman S, Wansink B. Asking questions: The definitive guide to questionnaire design—for market research, political polls, and social and health questionnaires. San Francisco, CA: Jossey-Bass. 2004.
28 U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation. HHS implementation guidance on data collection standards for race, ethnicity, sex, primary language, and disability status. 2011. Available from: https://aspe.hhs.gov/sites/default/files/documents/8c4525c504acc3b1bac16586119ce729/dhhs-implementation-guidance-data-collection-standards.pdf.
29 Wright T, Klein M, Wieczorek J. A primer on visualizations for comparing populations, including the issue of overlapping confidence intervals. Am Stat 73(2):165–78. 2019.