# Appendix IV. Data Tables

Tables I and II are data tables for Figures 1 and 2, respectively.

Table I

Weighted percent distribution of all sampled physicians and respondents, by selected physician characteristics: National CLAS Physician Survey, 2016

Physician characteristic from sample frame^1^ (variable name) | All sampled physicians using sample weights | | Respondents using sample weights | | | Respondents using final weights
Physician characteristic from sample frame^1^ (variable name) | Weighted percent | Standard error | Weighted percent | Standard error | Standardized bias^2^ | Weighted percent | Standard error | Standardized bias^2^
Sex (PHYSEX)
Female | 35.0 | 1.3 | 34.8 | 3.3 | 0.00 | 34.6 | 3.3 | 0.01
Male | 65.0 | 1.3 | 65.2 | 3.3 | 0.00 | 65.4 | 3.3 | 0.01
Age (recoded PYOB)
Younger than 50 | 41.4 | 1.4 | 30.3 | 3.1 | 0.23 | 33.8 | 3.4 | 0.15
50 and older | 58.6 | 1.4 | 69.7 | 3.1 | 0.23 | 66.2 | 3.4 | 0.15
Metropolitan status
Metropolitan statistical area | 93.3 | 0.7 | 92.7 | 2.0 | 0.02 | 93.0 | 2.0 | 0.01
Nonmetropolitan statistical area | 6.7 | 0.7 | 7.3 | 2.0 | 0.02 | 7.0 | 2.0 | 0.01

1 Information from the master files of the American Medical Association and the American Osteopathic Association.

2 Calculated using the formula: (|Weighted percentage of respondents − Weighted percentage of all sampled physicians|)/(sqrt(Weighted percentage of all sampled physicians • (100% − Weighted percentage of all sampled physicians)))

NOTE: CLAS is culturally and linguistically appropriate services.

SOURCE: National Center for Health Statistics, National CLAS Physician Survey, 2016.

Table II

Comparing final estimates between 2016 National CLAS Physician Survey and 2016 National Ambulatory Medical Care Survey

Physician characteristic from sample frame^1^ (variable name) | 2016 National CLAS Physician Survey | | 2016 NAMCS
Physician characteristic from sample frame^1^ (variable name) | Weighted percent | Standard error | Weighted percent | Standard error
Total | 100.0 | … | 100.0 | …
Sex (PHYSEX)
Female | 34.6 | 3.3 | 30.0 | 1.7
Male | 65.4 | 3.3 | 70.0 | 1.7
Age (recoded PYOB)
Younger than 50 | 33.8 | 3.4 | 37.6 | 1.8
50 and older | 66.2 | 3.4 | 62.4 | 1.8
Metropolitan status
Metropolitan statistical area | 93.0 | 2.0 | 92.4 | 1.0
Nonmetropolitan statistical area | 7.0 | 2.0 | 7.6 | 1.0

… Category not applicable.

1 Information from the master files of the American Medical Association and the American Osteopathic Association.

NOTES: CLAS is culturally and linguistically appropriate services. NAMCS is National Ambulatory Medical Care Survey.

SOURCES: National Center for Health Statistics, National CLAS Physician Survey, 2016, and National Ambulatory Medical Care Survey, 2016.