# Appendix II. National CLAS Physician Survey Objectives and Related Item Descriptions

Table

National CLAS Physician Survey items and corresponding survey objective or National CLAS Standard

Survey objective and enhanced National CLAS Standard | Item number | Item description
Survey objective
1. What is the nature and extent of ambulatory care provider awareness and knowledge of the National CLAS Standards? | 35, 36 | Awareness of the National CLAS Standards, practice's adoption of the National CLAS Standards
2. What is the nature and extent of ambulatory care provider implementation of culturally and linguistically appropriate services? | 11–34 | Written policy on CLAS; available free language-assistance services; interpreter use and material availability for patients with limited English proficiency, fluency in other languages; comfort providing care in another language; physician knowledge of patients' beliefs, customs, and values; consideration of cultural factors when assessing, diagnosing, and treating patients and when conducting health education; frequency of practice assessment of CLAS; attitudinal questions about both the expected outcomes of providing culturally and linguistically appropriate services; effect of factors that help or hinder the provision of CLAS
3. What factors enable or hinder the provision of culturally and linguistically appropriate services in ambulatory care settings? | 30–34 | Effect of factors that help or hinder the provision of CLAS
Enhanced National CLAS Standard
Principal standard: | 6–34, 36–38 | …
1. Provide effective, equitable, understandable, and respectful quality care and services that are responsive to diverse cultural health beliefs and practices, preferred languages, health literacy, and other communication needs. | 19–22, 24–29, 30–34 | Consideration of cultural factors when assessing, diagnosing, and treating patients and when conducting health education; attitudinal questions about expected outcomes of providing CLAS; effect of factors that help or hinder the provision of CLAS
Governance, leadership, and workforce: | 6–11, 36 | …
2. Advance and sustain organizational governance and leadership that promote CLAS and health equity through policy, practices, and allocated resources. | 11, 36 | Written policies regarding CLAS; practice's adoption of the National CLAS Standards
3. Recruit, promote, and support a culturally and linguistically diverse governance, leadership, and workforce that are responsive to the population in the service area. | 9–11 | Training in cultural competency required for hire; practice makes available cultural competency training; written policies regarding CLAS
4. Educate and train governance, leadership, and workforce in culturally and linguistically appropriate policies and practices on an ongoing basis. | 6–10 | Training in cultural competency in clinical training, medical school, and in the last 12 months
Communication and language assistance: | 12–17 | …
5. Offer language assistance to people who have limited English proficiency or other communication needs, at no cost to them, to facilitate timely access to all healthcare and services. | 12–14 | Format of printed materials for patients with limited English proficiency; available free language-assistance services; interpreter use for patients with limited English proficiency; types of interpreters used
6. Inform all people of the availability of language-assistance services clearly and in their preferred language, verbally and in writing. | 14, 16, 17 | Interpreter use for patients with limited English proficiency; types of interpreters used; physician fluency in languages other than English; number of languages the physician is comfortable using to provide healthcare services
7. Ensure the competence of people providing language assistance, recognizing that the use of untrained people or minors as interpreters should be avoided | 14, 16, 17 | Interpreter use for patients with limited English proficiency; types of interpreters used; physician fluency in languages other than English; number of languages the physician is comfortable providing healthcare services
8. Provide easy-to-understand print and multimedia materials and signage in the languages commonly used by the populations in the service area | 12, 13, 15 | Format of printed materials for patients with limited English proficiency; available free language-assistance services; materials available for patients with limited English literacy
Engagement, continuous improvement, and accountability: | 11, 18, 23, 36–38 | …
9. Establish culturally and linguistically appropriate goals, policies, and management accountability, and include them the organization’s planning and operations. | 11, 36 | Written policy on CLAS; practice's adoption of National CLAS Standards
10. Conduct ongoing assessments of the organization’s CLAS-related activities and integrate CLAS-related measures into measurement and continuous quality improvement activities. | 18, 23, 37, 38 | Physician knowledge of patient health beliefs, customs and values; frequency the practice assesses CLAS; recording of patient characteristics related to ethnicity, race, culture, and language
11. Collect and maintain accurate and reliable demographic data to monitor and evaluate the impact of CLAS on health equity and outcomes and to inform service delivery. | 37, 38 | Recording of patient characteristics related to ethnicity, race, culture and language
12. Conduct regular assessments of community health assets and needs and use the results to plan and implement services that respond to the cultural and linguistic diversity of populations in the service area. | --- | ---
13. Partner with the community to design, implement, and evaluate policies, practices, and services to ensure cultural and linguistic appropriateness. | --- | ---
14. Create conflict and grievance resolution processes that are culturally and linguistically appropriate to identify, prevent, and resolve conflicts or complaints. | --- | ---
15. Communicate the organization's progress in implementing and sustaining CLAS to all stakeholders, constituents, and the general public. | --- | ---
Items to determine eligibility or are required for weighting: | … | …
Eligibility | 2–4 | Physician specialty; direct patient care; setting where the physician sees the most patients
Weighting | 2, 5 | Physician specialty; setting where the physician sees the most patients

… Category not applicable.

--- Information not available; not captured in National CLAS Physician Survey items.

NOTE: CLAS is culturally and linguistically appropriate services.

SOURCES: U.S. Department of Health and Human Services, Office of Minority Health; and National Center for Health Statistics, National CLAS Physician Survey, 2016.