# Conclusion

Ambulatory care providers serve as a critical access point of care for many diverse populations. Through the provision of CLAS, they can reduce longstanding health disparities. The National CLAS Physician Survey was the first national survey to collect data that assessed the current practices, showed areas where physicians may be aware of and practicing the standards, and showed potential gaps among a nationally representative sample of office-based physicians. The survey is designed to provide accurate, reliable, and timely findings on key factors related to providing CLAS in ambulatory care settings that can better inform health policy, medical practice, quality-of-care research, education for health professionals, and future evaluations of CLAS. It will produce not only the first nationally representative results on CLAS in physician offices, but also baseline results for benchmarking the progress of meeting the key objectives of the National CLAS Standards among office-based physicians. The findings from the National CLAS Physician Survey will describe how the National CLAS Standards have been implemented by office-based physicians and may inform future policy discussions and development.