# Guidelines for Data Use

With the goal of mutual benefit, NCHS requests that recipients of data files use them for specific purposes.

Any published work using the National CLAS Physician Survey should acknowledge NCHS as the original source. The suggested citation, ‘‘Data Source: National Center for Health Statistics, National Culturally and Linguistically Appropriate Services Survey for Office-based Physicians, 2016’’ should appear at the bottom of all tables. Published work using the data should also include a disclaimer that credits any analyses, interpretations, or conclusions to the author and not to NCHS, which is responsible only for the initial data. Consumers who wish to publish a technical description of the data should make a reasonable effort to ensure that the description is consistent with that published by NCHS.

The Confidential Information Protection and Statistical Efficiency Act and the Public Health Service Act (Section 308d) require that these data collected by NCHS should be used only for health statistical reporting and analysis. Any effort to determine the identity of any reported case is prohibited by these laws. NCHS takes extraordinary measures to assure that the identity of survey subjects cannot be disclosed. All direct identifiers, as well as any characteristics that might lead to identification, have been omitted from the data set. Any intentional identification or disclosure of a person or establishment violates the assurances of confidentiality given to the providers of the information. As a result, users must:

- Use the data in this data set for statistical reporting and analysis only
- Make no use of the identity of any person discovered, inadvertently or otherwise, and advise the Director of NCHS of any such discovery (301–458–4500)
- Not link this data set with individually identifiable data from any other NCHS or non-NCHS data sets

Use of the data set signifies users’ agreement to comply with these statutory-based requirements.