# Data Access

Data users can obtain the National CLAS Physician Survey public-use file and the documentation for the data file on the NAMCS website: https://archive.cdc.gov/www_cdc_gov/nchs/ahcd/datasets-documentation-related-archived.htm.

Additionally, a restricted data file is available at the Research Data Center. More information about accessing data at the Research Data Center is available from: https://www.cdc.gov/rdc/?CDC_AAref_Val=https://www.cdc.gov/rdc/index.htm. Data from the two National CLAS Physician Survey questions that are included in the 2015 and 2016 NAMCS physician induction interview are available in the Research Data Center. Data users with questions may contact the National Center for Health Statistics, Division of Health Care Statistics, Data Analytics and Production Branch at 301–458–4600 or ambcare@cdc.gov.