# Item Nonresponse

Item nonresponse occurs when a survey respondent does not answer one or more items on the questionnaire. Among the many reasons for item nonresponse are a) respondent refusal to answer certain items and b) incorrect following of the questionnaire flow by the respondent. Refusal to answer certain items could be due to the sensitive nature of the item, the respondent not knowing the answer to the item, or the respondent simply choosing not to respond. Incorrect questionnaire flow occurs when the respondent skips items that should have been answered or answers items that should have been skipped. Unweighted item nonresponse rates were 5.0% or less for all items except the items in Table E.

Table E

Questionnaire items with nonresponse rates greater than 5%, variable names, instructions, denominator, and unweighted percentage missing: National CLAS Physician Survey, 2016

Questionnaire number | Variable name | Relevant instructions or context and question text | Denominator | Percent missing
8a | CME12POP1-6 | Which of these population groups have been addressed in the training(s) for cultural competency in which you have participated in the past 12 months? | 81 | 8.6
8b | CME12AREA1-5 | Which of the following areas have been typically included in training(s) for cultural competency in which you have participated in the past 12 months? | 81 | 8.6
10 | OFFERTRG | How often does your practice offer or make available training in cultural competency? | 397 | 9.4
11a | AWAREPOLICY | If "yes" to CLASPOLICY (Does your practice have at least one written policy related to the provision of culturally and linguistically appropriate services?), if you work in a non-solo practice, how aware are you of your practice’s written policy related to culturally and linguistically appropriate services? | 168 | 16.1
14 | INTERP | Do you use interpreters when working with patients who have limited English proficiency? | 397 | 8.1
14a1 | INTERPTY1 | If "yes" to INTERP (Do you use interpreters when working with patients who have limited English proficiency?), when you use interpreters, how often do you use staff/contractor trained as a medical interpreter? | 340 | 17.1
14a2 | INTERPTY2 | If "yes" to INTERP (Do you use interpreters when working with patients who have limited English proficiency?), when you use interpreters, how often do you use bilingual staff? | 340 | 13.5
14a3 | INTERPTY3 | If ‘yes’ to INTERP (Do you use interpreters working with patients who have limited English proficiency?), when you use interpreters how often do you use the patient’s relative or friend? | 340 | 12.5
16 | LANGUAGE | Are you fluent in a language besides English? | 397 | 6.6
17 | LANGSERV | How many languages, other than English, do you feel comfortable enough to provide health care services? | 397 | 8.6
18 | KNOWBELIEFS | How knowledgeable are you of your patients’ health beliefs, customs, and values? | 397 | 7.1
30 | FORMALPOLICY | How has each of the following factors affected you in providing culturally and linguistically appropriate services to your patients—Formal policy? | 203 | 7.9
31 | RESOURCES | How has each of the following factors affected you in providing cultural and linguistically appropriate services to your patients?—Organizational resources | 250 | 8.4
32 | CULTRTRG | How has each of the following factors affected you in providing cultural and linguistically appropriate services to your patients?—Training in cultural competency | 234 | 10.3
33 | PATKNOW | How has each of the following factors affected you in providing cultural and linguistically appropriate services to your patients?—Personal knowledge about the prevailing beliefs, customs, norms, and values of the diverse groups in your patient load | 348 | 6.0
35a1–5 | CLASKNOW1—CLASKNOW5 | If CLASKNOW (How familiar are you with the National Standards for Culturally and Linguistically Appropriate Services in Health and Health Care [the National CLAS Standards]?), is "heard of it but do not know much about it," "know something about it," or "very familiar with it," how have you gained knowledge about the National CLAS Standards?—through initial employment orientation in my current organization; through other trainings such as in-service, continuing education, or professional development activities in my current organization; through attending a training/meeting/webinar outside of my current organization; through reading a report, publication, newsletter, or other materials publicly available; other | 142 | 30.3
36 | CLASADOPT | Has your practice adopted the National CLAS Standards? | 142 | 12.7
41a | … | What percent of your patient population is represented by each of the following categories? | 271 | 29.2
41a | PATHISPANICR | Hispanic or Latino, of any race | … | …
41a | PATAINALNR | American Indian or Alaska Native, not Hispanic or Latino | … | …
41a | PATASIANR | Asian, not Hispanic or Latino | … | …
41a | PATBLACKR | Black or African American, not Hispanic or Latino | … | …
41a | PATNHOPIR | Native Hawaiian or Other Pacific Islander, not Hispanic or Latino | … | …
41a | PATWHITER | White, not Hispanic or Latino | … | …
41a | PAT2MORER | Two or more races, not Hispanic or Latino | … | …
41a | PATDKNOWR | I don’t know | … | …
41 | PHYRACER | What is your race? | 397 | 7.3

… Category not applicable.

NOTE: CLAS is culturally and linguistically appropriate services.

SOURCE: National Center for Health Statistics, National CLAS Physician Survey public-use file documentation, 2016.

The denominators for the rates of missing values were adjusted to account for skip patterns in the questionnaire. For example, only questionnaires from physicians who used interpreter services were included in the calculation of item nonresponse on the items concerning how often the physician used various types of interpreters.