# Survey Planning and Development

## Creation of Draft Questionnaire

A review of the scientific literature was conducted to identify relevant studies on the topics of culturally and linguistically appropriate health services, cultural competency training, and awareness and adoption of National CLAS Standards. Different combinations of the following keywords were used as search terms in Google Scholar and PubMed: “culturally and linguistically appropriate services,” “cultural competence,” “National CLAS Standards,” “physician survey,” and “health care provider survey.” Only peer-reviewed articles published in English were included. No publication date restrictions were imposed.

The literature review identified five relevant survey and assessment instruments published in peer-reviewed scientific journals. The five survey and assessment instruments were the Cultural Competence Self-Assessment Questionnaire (CCSAQ) (16,17), Tool for Assessing Cultural Competence Training (TACCT) (18), Cultural Competence Assessment (CCA) (19), Cultural Competence Health Practitioner Assessment (CCHPA) (20), and Cultural Assessment Survey (CAS) (21,22) (Table B).

Table B

Key surveys and instruments from literature review to identify relevant studies on topics of culturally and linguistically appropriate health services, cultural competency training, and awareness and adoption of National CLAS Standards

Instrument name | Description | Citation
Cultural Competence Self-Assessment Questionnaire (CCSAQ) | CCSAQ and its modified version were designed specifically for child- and family-serving agencies to determine their strengths and weaknesses in cross-cultural services. Both questionnaires have two parts (one for direct service providers and another for administrative staff) that contain items about bilingual staff, use of interpreters, record of patient demographics, CLAS policies, and provider knowledge of values and beliefs regarding care delivery to a culturally diverse group. | Mason JL. Cultural competence self-assessment questionnaire: A manual for users. Portland State University, Research and Training Center on Family Support and Children's Mental Health. 1995Godkin MA, Savageau JA. The effect of a global multiculturalism track on cultural competence of preclinical medical students. Fam Med 33(3):178–86. 2001.
Tool for Assessing Cultural Competence Training (TACCT) | TACCT is a self-administered assessment tool designed to examine medical school curriculum on cultural competence training. The survey assesses the training of physicians, covering cross-cultural clinical skills like working with interpreters and respecting different patient’s values, cultures, and beliefs. | Association of American Medical Colleges. Tool for assessing cultural competence training. 2016. Available from: https://www.aamc.org/system/files/c/2/54344-tacct_pdf.pdf.
Cultural Competence Assessment (CCA) | CCA was designed to measure cultural competence specifically among healthcare providers and staff in community hospice care settings. Despite its limited scope in hospice settings, many of the items, including cultural awareness and cultural competent behaviors, were aligned with the National CLAS Standards domains. | Schim SM, Doorenbos AZ, Miller J, Benkert R. Development of a cultural competence assessment instrument. J Nurs Meas 11(1):29–40. 2003.
Cultural Competence Health Practitioner Assessment (CCHPA) | CCHPA is a web-based instrument designed for health professionals to self-assess their capacity to deliver care to a culturally diverse population and promote cultural competence to reduce health disparities among racial and ethnic groups. CCHPA had items on provider knowledge of values and beliefs regarding care delivery to a culturally diverse group, an aspect that is similar to items from CCSAQ. | The National Center for Cultural Competence. Report of significant accomplishments for the National Center for Cultural Competence. Georgetown University Center for Child and Human Development. 2011.
Cultural Assessment Survey (CAS) | CAS was designed to evaluate the attitudes of underserved populations among preclinical and clinical medical students. It was initially used to compare the responses of students who participated in an elective that involved working internationally with underserved populations with those who did not participate in the international elective. The item from CAS on how well the participant felt they could incorporate culturally relevant information into a treatment plan was well-aligned with the National CLAS Standards domains. | Godkin M, Savageau J. The effect of medical students' international experiences on attitudes toward serving underserved multicultural populations. Fam Med 35(4):273–8. 2003.Gozu A, Beach MC, Price EG, Gary TL, Robinson K, Palacio A, et al. Self-administered instruments to measure cultural competence of health professionals: A systematic review. Teach Learn Med 19(2):180–90. 2007.

NOTES: CLAS is culturally and linguistically appropriate services. Google Scholar and PubMed were used with the following search terms: culturally and linguistically appropriate services, cultural competence, National CLAS Standards, physician survey, and health care provider survey. Only peer-reviewed articles published in English were included. No publication date restrictions were imposed.

SOURCES: "Cultural Competence Self-assessment Questionnaire: A Manual for Users"; "The Effect of a Global Multiculturalism Track on Cultural Competence of Preclinical Medical Students"; "Tool for Assessing Cultural Competence Training"; "Development of a Cultural Competence Assessment Instrument"; "Report of Significant Accomplishments for the National Center for Cultural Competence"; "The Effect of Medical Students' International Experiences on Attitudes Towards Serving Underserved Multicultural Populations"; "Self-administered Instruments to Measure Cultural Competence of Health Professionals: A Systematic Review."

None of these survey and assessment instruments comprehensively incorporated the multiple domains of the National CLAS Standards (Table A). CCSAQ contained the most relevant items consistent with the key objectives of the National CLAS Physician Survey; however, CCSAQ and its modified version focus narrowly on race and ethnicity rather than broadly on diverse cultural characteristics, health beliefs, literacy, and language preferences as defined by the National CLAS Standards. TAACT was designed to assess educational curricula rather than providers’ experiences and practices in cultural and linguistic competency. CCA was designed to assess components of cultural competence, including cultural awareness, cultural sensitivity, and cultural competence behaviors in hospice workers. CCA lacked questions about cultural competence: workforce training, workforce education, organizational governance, leadership, and National CLAS Standards awareness. CCHPA focused on self-assessment of health professionals regarding their cultural competence, and CAS was designed to evaluate attitudinal differences among medical students. Neither CCHPA nor CAS were designed for survey data collection.

As a result, a new survey needed to be developed. A draft version of the National CLAS Physician Survey was developed based on the content of the five existing instruments, the three key survey objectives, and the 15 domains of the National CLAS Standards (Table A). Through a repetitive (iterative) process, the Office of Minority Health and the National Center for Health Statistics (NCHS) decided on the content of the draft survey, the ordering and phrasing of the items, and the appropriateness of the response categories. This draft version was then refined through cognitive interview testing.

## Cognitive Interview Testing

Comprehension of questionnaire items for the National CLAS Physician Survey was assessed using cognitive interview testing, which allowed for understanding burden and potential response errors. The testing was approved by the NCHS Ethics Review Board (23). The methodology used was based on a qualitative question-evaluation method designed to identify question-response problems and examine the construct validities of survey questions (24–26). A separate Q-Bank report, from the NCHS Collaborating Center for Questionnaire Design and Evaluation Research, provides details on the cognitive testing of the content of the National CLAS Physician Survey (instructions, sections, questions, and response categories) using a paper mode of data collection (23). A separate assessment tested the usability of the web format of the questionnaire. Both the paper and web formats of the questionnaire had the same content, question phrasing, and response categories.

### Results and Recommendations From Cognitive Interview Testing

Cognitive interview testing identified the following three emergent themes about participant difficulties answering the draft National CLAS Physician Survey: 1) understanding the definition of culture and cultural competency training; 2) differentiating formal from informal training and policies; and 3) interpreting the questions universally for all patients or situationally for specific groups of patients (23).

The National CLAS Physician Survey had a series of questions about training in cultural competency; these are related to the first theme. These questions ask whether the respondent has ever received training in cultural competency, whether they participated in training in cultural competency in the past 12 months, the population groups that the training included, the specific topics covered in the training, and whether the training was related to credentialing. The challenges with these questions were related to the setting in which the training occurred (23). Respondents younger than age 50 typically considered training in cultural competency as part of medical school or residency education (23). However, respondents age 50 and older typically thought of training in cultural competency as continuing medical education. Not providing a definition for the term “training in cultural competency” led to respondent uncertainty about what activities qualified for the series of questions that asked about it. Consequently, a definition was included in the final questionnaire to reduce respondent uncertainty: Training in cultural competency includes educational opportunities that address topics of culture in settings such as employee orientation, continuing medical education, conferences, or webinars.

The National CLAS Physician Survey included several questions about training and policies related to cultural competency and CLAS that did not specify the formality (or informality) of the training or policy, representing the second theme. Differentiating formal and informal training was a challenge for respondents, specifically, uncertainty about whether the questions referred to formal mandated training or informal voluntary training. Also, incomplete understanding of what training in cultural competency was added to question complexity. Providing a definition that described both formal and informal training in cultural competency resolved this confusion. The formal and informal nature of training as it related to the types of translators used also caused difficulty for respondents. This issue was resolved by specifying translator training in the three response options, "staff/contractor trained as a medical interpreter," "bilingual staff," or "patient's relative or friend."

The questions on policies related to training for new hires and the existence and awareness of policies about the provision of CLAS also posed challenges. Respondents had difficulty determining whether survey questions that referenced policy were referring to formal or informal policies. Many respondents defined formal policies as being written, while informal policies were not. Several respondents assumed the questions referred to formal policies and were uncertain whether the questions were to be answered regarding the practice’s policies or the policies of the larger organization. As a result, the question about having “at least one policy” related to CLAS was revised to ask about having “at least one formal written policy.” For the question about whether factors affected the provision of CLAS, policy (informal or formal) was changed to “formal written policy.”

The final emergent theme was related to respondent challenges differentiating universal and situational interpretation of questions. The questions about whether the respondent considered race, ethnicity, or other cultural factors during assessment of patient needs, diagnosis, and treatment or when conducting health education (Appendix I, Questions 19–22) posed challenges as respondents expressed that there was not a single response for all situations. For example, certain conditions have no known racial, ethnic, or cultural differences in diagnosis or treatment. Thus, a physician may diagnose and treat all patients with that condition the same, regardless of racial, ethnic, or cultural differences. However, for conditions that do differ in diagnosis or treatment by racial, ethnic, or cultural groups, a physician may consider race, ethnicity, or cultural factors on a situational basis when diagnosing or treating patients. These situational differences made it difficult to decide the appropriate responses.

## Finalization of National CLAS Physician Survey Questionnaire

The key changes made between the original draft and the final questionnaire are shown in Table C. The changes from the original to revised questionnaire and then to the final version were either related to the themes described previously or to improve clarity, reduce burden, or meet reporting standards. The questions for the final version were reordered for various reasons, including improvement of questionnaire flow, sequential placement of eligibility questions early in the questionnaire, and placement of complex questions at the end of the questionnaire.

Table C

Key modifications to National CLAS Physician Survey questionnaire from original and revised versions to final version: National Culturally and Linguistically Appropriate Services Physician Survey, 2016

Type of modification | Original version | Revised version | Final version
Training in cultural competency theme | After your clinical training, have you participated in training for cultural competency such as continuing education? | After your clinical training, have you participated in training for cultural competency such as continuing education or continuing medical education? | After medical school and residency, have you participated in training for cultural competency such as continuing medical education (CME)?
Training in cultural competency theme | Did you receive any training in cultural competency in your clinical training programs, including medical school and residency? | … | Did you receive any training in cultural competency in your clinical training programs, including medical school and residency? Training in cultural competency includes educational opportunities that address topics of culture in settings such as employee orientation, continuing medical education, conferences, or webinars.
Formal and informal theme | Does your practice have at least one policy in place related to the provision of culturally and linguistically appropriate services? | … | Does your practice have at least one written policy related to the provision of culturally and linguistically appropriate services?
Formal and informal theme | How has each of the following factors affected you in providing culturally and linguistically appropriate services to your patients? Policy (formal or informal) related to the provision of culturally and linguistically appropriate services | How has each of the following factors affected you in providing culturally and linguistically appropriate services to your patients? Policy (formal or informal) | How has each of the following factors affected you in providing culturally and linguistically appropriate services to your patients? Formal written policy
Rephrased for clarification | In what setting do you typically provide care to the most patients? | In what setting do you typically provide care to the most patients? (Check all that apply) | In what setting do you typically provide care to the most patients? (Check all that apply)
Rephrased for clarification | For the remaining questions, please provide answers reflecting your experiences at this location. | … | For the remaining questions, please provide answers reflecting your experiences at the location where you see the most patients that are not in hospital emergency or hospital outpatient departments. If you feel you see the same number of patients at more than one location, please select one.
Rephrased for clarification | This survey asks about ambulatory care, that is, care for patients receiving health services without admission to a hospital or other facility. | … | This survey is affiliated with the National Ambulatory Medical Care Survey (NAMCS). The survey should only be completed by the physician to whom it is addressed. The purpose of this survey is to understand the provision of culturally and linguistically appropriate services among office-based physicians. Culturally and linguistically appropriate services consider cultural health beliefs, practices, and preferred languages associated with various racial, ethnic, linguistic, or religious groups. Your participation in this survey is voluntary and greatly appreciated. Your answers are completely confidential. If you have questions or comments about this survey, please call xxx-xxx-xxxx.
Rephrased for clarification | How many years have you been providing direct care for ambulatory care patients? | … | Including residency, how many years have you been providing direct care for patients in an office-based setting?
Rephrased for clarification | How aware are you of your practice’s culturally and linguistically appropriate services-related policy? | … | If you work in a non-solo practice, how aware are you of your practice’s written policy related to culturally and linguistically appropriate services?
Rephrased for clarification | Which methods are used to inform your patients of free language-assistance services available in your practice? (Check all that apply) | Which of these free language-assistance services are available to patients in your practice? (Check all that apply) | Which of these free language-assistance services are available to patients in your practice? (Check all that apply)
Rephrased for clarification | Which methods are used to inform your patients of free language-assistance services available from external sources? (Check all that apply) | Which of these free language-assistance services are available to patients from external sources? (Check all that apply) | Item was deleted
| How often do you use each type of interpreter? Response choices: Trained staff or contractor, Patient's relative or friend | When you use interpreters, how often do you use each type? Response choices: Trained staff, Contractor, Patient's relative or friend | When you use interpreters, how often do you use each type? Response choices: Staff/contractor trained as a medical interpreter, Bilingual staff, Patient's relative or friend
| What information does your practice collect on your patients’ culture and language characteristics? (Check all that apply) | What information does your practice record on your patients’ culture and language characteristics? (Check all that apply) | What information does your practice record on your patients’ culture and language characteristics? (Check all that apply)
| Help-seeking practices? (Help-seeking practices: process of actively seeking help from others, whether it be informally through friends/family or professionally) | Help-seeking practices? (Process of actively seeking help from others, whether it be informally through friends/family or professionally) | Item was deleted
| How has each of the following factors affected you in providing culturally and linguistically appropriate services to your patients? Response choices: Helped, No effect, Hindered, Not applicable | How has each of the following factors affected you in providing culturally and linguistically appropriate services to your patients? Response choices: Helped, No effect, Prevented, Not applicable | How has each of the following factors affected you in providing culturally and linguistically appropriate services to your patients? Response choices: Helped, Helped a little, Did not help, Not applicable
| What outcome(s) do you expect by providing culturally and linguistically appropriate services to your patients? (Check all that apply) | … | Mark your agreement or disagreement with the following statements. {Strongly disagree, Disagree, Agree, Strongly agree} By providing culturally and linguistically appropriate services to my patients I expect:
| Satisfaction with services | … | Improved patient satisfaction with the services provided
| Comprehension of treatment and lifestyle recommendations | … | Improved comprehension of treatment and lifestyle recommendations
| Health status/outcomes | … | Item was deleted
| Adherence to treatment and lifestyle recommendations | … | Better adherence to treatment and lifestyle recommendations
| Improved patient trust | … | Improved patient trust
| Improved quality of patient care (e.g., diagnostics, communication, treatment) | … | Improved quality of patient care (e.g. diagnostics, communication, treatment)
| Decreased likelihood of liability/malpractice claims | … | Decreased likelihood of liability/malpractice claims
| Other(s) (Please specify): _________________ | … | Item was deleted
| I do not expect any outcomes in providing culturally and linguistically appropriate services to my patients. | … | Item was deleted
| I do not provide culturally and linguistically appropriate services. | … | Item was deleted
To meet reporting standards | What is your ethnicity? | … | Are you Hispanic, Latino/a, or Spanish Origin? (Check all that apply)
| Not Hispanic or Latino | … | No, not of Hispanic, Latino/a, or Spanish origin
| Hispanic or Latino | … | Yes, Another Hispanic, Latino/a or Spanish origin Yes, Cuban Yes, Mexican, Mexican American, Chicano/a Yes, Puerto Rican
| What is your race? (Check all that apply) | … | What is your race? (Check all that apply)
| American Indian and Alaska Native | … | American Indian or Alaska Native
| Black or African American | … | Black or African American
| Asian | … | Asian Indian Chinese Filipino Japanese Korean Vietnamese Other Asian
| Native Hawaiian or Other Pacific Islander | … | Guamanian or Chamorro Native Hawaiian Samoan Other Pacific Islander
| White | … | White
Definition moved for clarification | Definition of culture was misplaced (after first mention) | Definition placed immediately before the first use of the term | Definition placed immediately before the first use of the term
Definition moved for clarification | Definition of culturally and linguistically appropriate services was misplaced (after first mention) | Definition placed immediately before the first use of the term | Definition placed immediately before the first use of the term
Definition moved for clarification | Universal symbols | Universal symbols (A sign recognized by most people. Example: a square around a plus sign for first aid.) | Universal symbols (A sign recognized by most people. Example: a square around a plus sign for first aid.)
Definition moved for clarification | Infographics | Infographics (A visual image such as a chart or diagram used to represent information or data.) | Infographics (A visual image such as a chart or diagram used to represent information or data.)
Skip pattern changes to correctly capture response | If the respondent answered no to “Are you fluent in a language besides English?” he or she would skip the question “How many languages, other than English, do you feel comfortable enough to provide healthcare services?” | … | Regardless of response to “Are you fluent in a language besides English?” respondent will be asked, “How many languages, other than English, do you feel comfortable enough to provide healthcare services?”
Skip pattern changes to reduce burden | Respondents who answered, never heard of it to “How familiar are you with the National Standards for Culturally and Linguistically Appropriate Services in Health and Health Care (the National CLAS Standards)?” were asked to answer the question, “Has your practice adopted the National CLAS Standards?” | … | Respondents who answered, never heard of it to “How familiar are you with the National Standards for Culturally and Linguistically Appropriate Services in Health and Health Care (the National CLAS Standards)?” no longer answer the question, “Has your practice adopted the National CLAS Standards?”
Skip pattern changes to reduce burden | Respondents who did not check that they collect information on patient “race/ethnicity” would be asked to answer the question about the race and ethnic backgrounds of the patient population. | … | Respondents who answer no or don’t know to, “Does your practice record your patients’ race or ethnicity?” no longer answer questions about patient race and ethnicity.
Skip pattern changes to correctly capture response | What information does your practice record on your patients’ culture and language characteristics? (Check all that apply) | … | Does your practice record your patients’ race or ethnicity?
Skip pattern changes to correctly capture response | Race/Ethnicity | … | Yes No [SKIP to item 38] I don’t know [SKIP to item 38]

… Category not applicable; the question wording was not revised.

NOTE: CLAS is culturally and linguistically appropriate services.

SOURCE: National Center for Health Statistics, National CLAS Physician Survey questionnaire, 2016.

After these revisions were made, the final version of the questionnaire had 42 items, capturing information on the respondent’s demographic and practice characteristics, cultural competency training, provision of CLAS, and awareness of the National CLAS Standards (Appendix I). Each item on the questionnaire corresponds to a specific domain of the enhanced National CLAS Standards and to a key objective of the survey (Appendix II), except for items related to eligibility, weighting, and physician demographics. The final questionnaire was estimated to take about 9.5 minutes to complete.

The questions used to determine eligibility (questions 2, 3, and 4) and weight the data (questions 2 and 5) were placed at the beginning of the questionnaire to ensure that this required information was available for all respondents. This placement also reduced the burden on ineligible respondents. Survey questions 6–36 address the enhanced National CLAS Standards. The goal was to not bias the respondents’ subsequent responses to questions by asking about the National CLAS Standards early in the questionnaire. As a result, those questions were placed near the end of the questionnaire, contrary to the survey methodology recommendation to place the most important questions first (27).

## Representation of Enhanced National CLAS Standards in Items of National CLAS Physician Survey

Appendix II shows how the enhanced National CLAS Standards are represented within the content of the National CLAS Physician Survey. Standard 1 of the enhanced National CLAS Standards is the Principal Standard. Some of the questions in the National CLAS Physician Survey, especially the attitudinal ones, fit best with this overarching standard. Specifically, questions 19–22 ask about the consideration of cultural factors when assessing, diagnosing, and treating patients and when conducting health education. In addition, attitudinal questions about both the expected outcomes of providing CLAS (questions 24–29) and the effect of factors that help or hinder the provision of CLAS (questions 30–34) are included.

Standards 2–4 address governance, leadership, and workforce. Standard 2 is addressed in questions 11 and 36: question 11 is about written CLAS policies at the practice and the physician’s knowledge of the policy (question 11a). Question 36 asks whether the physician’s practice has adopted the National CLAS Standards. Standard 3 is associated with questions 9–11. Standard 4 is captured in questions 6–10. These questions ask about training in cultural competency. One question specifically asks whether training is required for physician new hires (question 9).

Standards 5–8 address communication and language assistance. Each of the standards in this domain are addressed in the National CLAS Physician Survey. Standard 5 is captured in questions 12–14. Question 12 asks about printed materials available for patients with limited English literacy. Question 13 asks about the free language-assistance services that are available at the physician’s practice. Question 14 asks whether interpreters are used for patients who have limited English proficiency. Standards 6 and 7 are assessed in questions 14, 16, and 17. Question 14 asks whether interpreters are used and, if so, the types of interpreters used (question 14a). Question 14a asks whether staff and contractors trained as medical interpreters, bilingual staff, or the patient’s relative or friend are used. Question 16 asks about the physician’s fluency in languages other than English. Question 17 asks the number of languages the physician feels comfortable using to provide healthcare services. The physician fluency questions (questions 16 and 17) were moved from the beginning of the questionnaire to the middle of the questionnaire with the other language questions to improve flow and cohesiveness. The final standard of this domain, Standard 8, is addressed in questions 12, 13, and 15. Questions 12 and 13 ask about items for patients with limited English literacy, which include universal symbols and infographics (question 12) and multimedia materials, such as recorded messages and translated signs (question 13). Question 15 asks about the types of materials available for patients in languages other than English.

Standards 9–15 address engagement, continuous improvement, and accountability. Standards 9–11 are captured in the survey. Standard 9 is captured in questions 11 and 36 on policy implementation. Standard 10 is addressed in questions 18, 23, 37, and 38. Question 18 is about the physician’s knowledge of patient health beliefs, customs, and values. The frequency at which the practice is assessed for the cultural and linguistic appropriateness of services is addressed in question 23. Recording of patient characteristics related to culture is asked in questions 37 and 38. Standard 11 is addressed in questions 37 and 38. Standards 12–15 are not represented in the National CLAS Physician Survey.

The remaining survey questions collect demographic information. The demographic questions (37–42) were placed at the end of the questionnaire, which is a common survey methodology practice (27). Question 37a asks for the percentage of the physician’s patient population by race and ethnicity. Initially, this question was considered too burdensome to ask physicians who may not know their patient population’s racial and ethnic composition. Because of this, it was recommended that a skip pattern be added so that those who indicated that they did not collect information on their patient population’s racial and ethnic composition would not be asked the more detailed question about race and ethnicity (question 37a). Physician demographics (sex, race, and ethnicity) are asked in questions 39–41. The race and ethnicity categories were revised to align with HHS implementation guidance on data collection standards for race, ethnicity, sex, primary language, and disability status (28). The final item on the questionnaire was a checkbox asking the respondent to “verify that this questionnaire was completed by the physician to whom it was addressed.” This statement and instructions that the questionnaire should be completed only by the physician to whom it was addressed were important factors considered during the development process. Using proxy respondents was inappropriate due to the nature of the questions and the inability of anyone other than the physician to respond accurately to the survey questions.