# Front Matter

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Health Care Statistics

Carol DeFrances, Ph.D., Director

Alexander Strashny, Ph.D., Associate Director for Science

For answers to questions about this report or for a list of reports published in these series, contact:

Information Dissemination Staff

National Center for Health Statistics

Centers for Disease Control and Prevention

3311 Toledo Road, Room 4551, MS P08

Hyattsville, MD 20782

Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/updates/.

## Acknowledgments

The 2016 National Culturally and Linguistically Appropriate Services Survey for Office-based Physicians was sponsored and funded by the U.S. Department of Health and Human Services Office of Minority Health. It was conducted by the National Center for Health Statistics as a supplement to the National Ambulatory Medical Care Survey. Data collection was conducted by SRA International.

Data file creation at the National Center for Health Statistics was completed by Kai Kang, Titi Okeyode, Thomas Socey, and Roberto Valverde. Analytic assistance was provided by Christopher Cairns. Statistical consultation was provided by Rebecca Hu, Van Parsons, Morgan Earp, Iris Shimizu, Roberto Valverde, and Guangyu Zhang. The report was edited and produced by National Center for Health Statistics' Office of Information Services, Information Design and Publishing staff: editor Danielle Taylor and typesetter and designer Michael W. Jones (contractor). Finally, the authors extend their appreciation to the physicians who participated in the survey.

Lacreisha Ejike-King is with the United States Public Health Service. Meena Khare retired from the National Center for Health Statistics while working on this project.