# 5 Conclusion

The generation of well-controlled and well-characterized radiofrequency radiation (RFR) exposures is a critical factor in carrying out experimental studies to assess the interactions between RFR and biological tissues. Such research requires the development of an exposure system that can generate radiofrequency (RF) signals that mimic human exposure, which can vary because of the continued use of frequencies and modulations in older cell phone technologies (2G, 3G, 4G long-term evolution [LTE]) and the implementation of evolving mobile communication technology (5G and beyond) that utilizes different frequencies and modulations.

The development of a small-scale RFR exposure system with expanded capabilities was a major goal for this investigative research to understand the effects of RFR exposure on biological responses in rats and mice. The studies reported herein were conducted by researchers in the Division of Translational Toxicology (DTT) at the National Institute of Environmental Health Sciences (NIEHS). These studies were not conducted as part of the National Toxicology Program (NTP).

This report describes the development of a small-scale exposure system by NIEHS/DTT that was based on the one used in previous NTP studies^12,13,15-18^ and presents data from short-term investigative studies on RFR exposure. Working with the same technical experts as those who supported the previous NTP toxicology and carcinogenesis studies, an RFR exposure system with four exposure chambers capable of housing 10 animals each was designed, constructed, and tested for its performance in generating the desired RFR exposures (i.e., RF field strength, uniformity, and homogeneity). Technical staff from the National Institute of Standards and Technology also independently tested the system to verify the RF field strengths, signal quality, and signal parameters recorded by the internal components of the exposure system in a process analogous to that used in the previous NTP studies.^12,13,17^ Field uniformity and signal quality were acceptable, and the overall conclusion of the technical experts was that the small-scale exposure system operated correctly and was capable of performing the exposure study.

The small-scale exposure system had greater flexibility for evaluating different characteristics of RF signals and increased functional capabilities compared to the system developed for the previous NTP studies.^17,18^ Although it was state of the art for the time, the exposure system used in the previous NTP studies was based on technology that was only capable of generating Global System for Mobile Communications (GSM)- and Code Division Multiple Access (CDMA)-modulated RF signals at 900 and 1,900 MHz, which are older, less used cell phone technologies such as 2G and 3G. Additionally, each chamber had to be permanently designated for a specific modulation at a specific frequency, and, as a result, a greater number of chambers was required. The new small-scale RFR exposure system described in this report was developed by NIEHS/DTT to overcome those limitations with a signal generator capable of generating a broader array of RF signals. In addition to the GSM and CDMA signals at 900 and 1,900 MHz used in the previous NTP studies, the small-scale exposure system could generate signals reflective of more current wireless communications (e.g., Third Generation Partnership Project [3GPP] LTE Frequency Division Duplex [FDD] and Time Division Duplex [TDD], LTE-Advanced, 3GPP FDD/ High-Speed Packet Access [HSPA]/HSPA+, GSM/Enhanced Data rates for GSM Evolution [EDGE]/EDGE Evolution, Time Division-Synchronous CDMA [TD-SCDMA], Wireless Local-area Network [WLAN]) with frequencies between 9 kHz and 3.2 GHz, modulations with base bandwidths of up to 120 MHz, and carrier frequencies of up to 3,200 MHz. With these broader exposure flexibilities, a single chamber could be used for different signal frequencies, and the same chambers could be used at different times for studies in different animal strains, with different signals, and at different frequencies. Chambers were also equipped with the ability to toggle between two different light sources—halogen-based incandescent bulbs in these NIEHS/DTT studies, for consistency with the light source in the previous NTP studies, and newer light emitting diode (LED) bulbs. In addition, the system was designed to accommodate video recording during RFR exposure to enable monitoring of animals during exposure. Recorded video was used to observe if there were any changes in animal activity associated with RFR exposure or the physical functioning of the system.

After development and verification of the new RFR exposure system, unanticipated challenges were encountered that required extensive technical expertise to resolve. Following successful completion of the mouse CDMA study but prior to conducting the rat studies, numerous system modifications were required. These modifications included the fabrication and testing of new cage lids, evaluation and modification of the animal drinking water system, and reprogramming of the stirrer operations. Additional technical issues occurred during the conduct of the rat studies that required continued remote support from the Foundation for Research on Information Technologies in Society (IT’IS).

The new small-scale RFR exposure system was used to conduct an array of studies to investigate the role of heat, stress, and specific exposure parameters on the underlying potential mechanisms of RFR-mediated toxicity and carcinogenicity. The overall goals of this investigative project included evaluating cellular and molecular changes of DNA damage in the heart, brain, liver, and blood; measuring real-time changes in physiological parameters and animal response to RFR exposure; and investigating newer telecommunications technologies. Four 5-day investigative studies (three in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and one in B6C3F1/N mice) were conducted by NIEHS/DTT to evaluate the performance of the new RFR exposure system; compare the function of the new exposure system with the original system used in the previous NTP studies; and evaluate the effects of RFR exposure on body weight, body temperature, and DNA damage, as well as observe animals during exposure using video cameras.

In these studies, evaluation of video from the cameras in the exposure chambers demonstrated no consistent, exposure-related, and visible changes in activity in either rats or mice the first time the system was activated, during subsequent system on/off transitions, or during the periods of exposure. It has been hypothesized that the RF signal itself, noise generated during exposure periods, or the physical motion of the chamber components, such as the stirrers that serve to generate a homogeneous RF field, may startle the animals or otherwise induce a stress response.^37-39^ A question raised during peer review of the previous NTP studies was whether the physical components of the reverberation chamber RFR exposure system or the signal itself had any effect on the animals. The previous NTP studies did not capture video of the animals during periods of exposure to observe changes that would indicate awareness of or reaction to RFR exposure; therefore, there was specific interest in capturing any awareness or reaction by the animals the first time they experienced the system’s activation and the slow physical rotation of the vertical and horizontal stirrers. The potential effect of RF signal, noise, or physical/mechanical activity during exposures has never been evaluated in toxicological studies of RFR in animals. The lack of observable reaction in the current studies using the small-scale system with RFR exposure levels up to 9 W/kg body weight (W/kg) in rats and 15 W/kg in mice suggests that operation of the system did not subject the animals to stress or discomfort.

A key goal for these investigative studies was to assess temperature changes during exposure, which was not conducted in the previous NTP chronic toxicity and carcinogenicity studies. The data generated by the data loggers and temperature chips during the rat and mouse studies were unusable.

Implanted data loggers were used to record changes in internal body temperature in real time while the RFR system was operational. The previously established method of temperature measurement using the implanted-temperature-chip approach required complete shutdown of the RFR system before animals could be assessed. After the system was shut down and chambers opened, a handheld sensor was used to collect individual animal temperatures from the implanted chips. Because animals are constantly thermoregulating, time between cessation of exposure and measurement of temperature could be a key factor affecting data collection and accuracy (as was the case with temperature-chip measurements in this study). The data loggers, if demonstrated as a viable method to collect body temperature, would allow for a robust real-time assessment of the effects of RFR exposure on body temperature during exposure. Unfortunately, data recorded by the data loggers in this study were inconsistent over short periods of time, and often not physiologically possible. As a result, the data-logger approach proved to be technically unfeasible.

As a component of the current NIEHS/DTT 5-day studies, the comet assay was used to explore whether genotoxic effects of RFR could be observed following a short duration of exposure. To reduce the influence of inter-animal variation, 10 animals per group were evaluated instead of 5, as was done for the previous 90-day NTP comet assay study. Exposure to RFR for 5 days did not induce DNA damage in brain cells (frontal cortex, hippocampus, and cerebellum), or in liver, heart, or blood cells of rats and mice. Equivocal results, showing limited statistically significant effects, were observed for male mouse liver cells (CDMA) and male rat hippocampal cells (GSM) in these 5-day studies. Although it is not possible to directly compare the 5-day and 90-day comet assay studies, it is interesting to note that a positive result for hippocampal cells from male rats exposed to CDMA was observed in the 90-day study. In addition, the unusually low baseline for the percent tail DNA reported for the frontal cortex of male mice in the chamber control group of the previous 90-day NTP study (1.32% ± 0.21% when 150 cells were assessed)^16^ was also observed in the current 5-day study for male mice (0.46% ± 0.11% for the room control group and 0.91% ± 0.10% for the chamber control group). These observations appear to be consistent with previous studies indicating that shorter durations of exposure may not induce significant levels of DNA damage.^40,41^

In summary, researchers at the NIEHS/DTT developed a small-scale RFR exposure system to investigate the effects of RFR exposure on biological responses in rats and mice and to better understand the potential mechanisms of RFR-mediated toxicity and carcinogenicity reported in the previous NTP studies. The investigative studies to test the exposure system found that the animals showed no visible response during operation of the system, and exposure to RFR for 5 days did not induce DNA damage in rats and mice.

These investigative studies of RFR exposure were technically challenging to conduct and, unfortunately, did not yield data useful for assessing body temperature in real time. Despite these difficulties, this small-scale RFR exposure system presents a prototype for investigative toxicological studies by researchers interested in conducting experimental RFR studies in rodent models. High-quality studies to understand the effects of RFR exposure on biological responses are needed given the widespread human exposure to RFR associated with cell phone use. This report presents information about the design and conduct of this novel, small-scale RFR exposure system to facilitate advancement in methodologies and raise awareness about technical challenges associated with studying RFR.