# 4 Five-day Investigative Studies in Rats and Mice

## 4.1 Introduction

After system installation, verification, and qualification were completed, a series of four 5-day studies was conducted in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats or B6C3F1/N mice. The goal of these studies was to further characterize radiofrequency radiation (RFR)-induced changes in body temperature and DNA damage observed in the previous National Toxicology Program (NTP) RFR studies and evaluate the use of new methods for collecting live, real-time data.

Changes in body temperature are important because the absorption of radiofrequency (RF) energy by biological tissues occurs in the form of heat transfer. It has been postulated that the absorption of RFR during exposure, even at power levels that do not lead to significant changes in body temperature, may constantly affect body temperature and challenge an animal’s ability to thermoregulate and cause changes through this constant thermal stress. To understand the role of heat in the underlying mechanism of RFR-induced effects, it is critical to assess the impact of RFR exposure on body temperature in real time. Two different methods for measuring body temperature were selected for use in these 5-day studies. The first method was an implanted temperature chip analogous to those used in the previous NTP studies. The temperature chips can report temperature but are not able to record to the device. Therefore, the exposure system must be stopped and a temperature reader brought in close proximity with each chip to detect and report temperature for manual recording. The temperature chip has been shown to be accurate, although it does not allow measurement of temperature during exposure. In addition, there was criticism of the previous NTP studies that these temperature chips implanted into the subscapular region do not accurately reflect a core body temperature change. To help address both of these limitations, National Institute of Environmental Health Sciences Division of Translational Toxicology (NIEHS/DTT) scientists selected a second method to measure body temperature using an implantable temperature device (i.e., data loggers) for use in these 5-day studies. The data loggers are able to record temperatures at programmable intervals onto the device, allowing observation of temperature changes during exposure. The data loggers were implanted within the peritoneal cavity and were anticipated to better reflect internal core body temperature.

One noted limitation of the previous NTP studies was the lack of visual assessment of animal behavior during periods of exposure, and especially the moment the animals experienced the system initiation for the first time as well as during transitions between on/off exposure periods. Increased incidences in pheochromocytomas and other neuroendocrine changes in male rats from the previous NTP RFR studies suggest that there may be a potential stress response. In the current NIEHS/DTT studies, video from cameras inside of the exposure chambers was assessed for visible signs of a physical response at activation of the exposure system or during exposure to RF signals. In addition, a separate group of room control animals was included in the studies to assess the impact of housing within the RFR exposure chambers. Animals in this group were not exposed to RFR and were not housed within the RFR exposure chambers themselves at any time but were present in the same room where the RFR exposure chambers were located.

## 4.2 Materials and Methods

### 4.2.1 Animal Source

Male and female Sprague Dawley rats were obtained from the testing facility’s holding colony, originally obtained from Envigo (Indianapolis, IN). Male B6C3F1/N mice were obtained from the testing facility’s holding colony, originally obtained from the NTP colony maintained by Taconic Biosciences, Inc. (Germantown, NY).

### 4.2.2 Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the testing facility (West Jefferson, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health and NIEHS/DTT animal care and use policies and applicable federal, state, and local regulations and guidelines.

### 4.2.3 Five-day Studies

#### 4.2.3.1 Exposure Level Selection Rationale

The previous NTP studies on RFR^12,13,15^ utilized whole-body exposure levels of 0, 3, 6, or 9 W/kg body weight (W/kg) for rats, and 0, 5, 10, or 15 W/kg for mice. In the prior NTP 5-day studies, exposure-related increases in body temperatures were observed at exposure levels ≥6 W/kg in aged male and female Sprague Dawley rats, with exposure levels above 10 W/kg inducing increases in body temperature (≤3°C) and mortality in aged rats.^15^ In the prior 28-day studies, reduced body weights and increased body temperature measurements occurred at 9 W/kg for rats; exposure to 6 W/kg resulted in some increases in core body temperature, but these increases were less than 1°C.^13^ In male and female mice exposed for 5 days to RFR up to 12 W/kg, only sporadic increases in body temperature were observed and these changes were independent of the sex or age of the animals.^15^

In the current NIEHS/DTT studies, 15 W/kg was selected as the highest exposure level for the mouse study. The maximum capacity of the exposure system to generate high RF fields was intentionally limited to an achievable exposure capacity of 15 W/kg for mice. Because of the system capacity limitations and results of the published 5-day studies,^15^ and the previous 28-day and 2-year NTP studies, the exposure levels selected for these NIEHS/DTT 5-day studies were 0, 3, 6, or 9 W/kg for rats and 0, 5, 10, or 15 W/kg for mice.

#### 4.2.3.2 Body Temperature Measurements

Prior to exposure, each animal was surgically implanted with a Star-Oddi nano-T temperature logger (data logger; Star-Oddi, Gardebaer, Iceland) in the intraperitoneal cavity and an Implantable Programmable Temperature Transponder (temperature chip; IPTT-300, Bio Medic Data Systems, Seaford, DE) in the subcutaneous interscapular region to monitor individual animal body temperature. Animals were allowed to recover for at least 13 days (rats) or 8 days (mice) before exposure began.

The data generated by the data loggers and temperature chips during the rat and mouse studies were unusable. Below is the rationale for not summarizing and interpreting each temperature data set.

The data loggers recorded animal body temperature continuously throughout the study. A review of the continuous temperature data from the data loggers showed there were numerous instances of implausible data points. For example, some data loggers recorded single time-point body temperatures that were not considered biologically plausible (e.g., as low as 32°C, which was considered implausibly low), or they showed changes in body temperature of several °C from one minute to the next.

The temperature chips did not record animal body temperature on the implanted device and required a temperature reader wand to be placed in proximity of the chip to report and manually record a temperature. Collection of these temperature data required the reverberation chambers to be opened and animals to be removed from their cages to record a body temperature. On study days 0, 2, and 4, body temperature measurements were taken from the temperature chips at 10 minutes prior to exposure, after the first 10 minutes following the start of exposure (mice only), and after 1, 4, and 20 hours of exposure; body temperatures were also recorded on study day 5 for female rats. The intention was for body temperatures to be recorded immediately after a 10-minute “on” period of RFR exposure. Due to a methodological error with the temperature chips, body temperatures were taken at time points relative to the start of exposure without taking into account the on/off cycling. A review of the collection times of individual animal temperature against the exposure period determined that the majority of temperature recordings were taken too long (e.g., >5 minutes) after the most recent 10-minute “on” period ended. Immediately after RFR exposure ends, animals thermoregulate and return to a baseline temperature very quickly. Temperature recordings taken more than 5 minutes after exposure has ended cannot be interpreted regarding the effect of RFR exposure on body temperature.

#### 4.2.3.3 Study Design

The rat and mouse studies were conducted between July 2020 and November 2021, as depicted in Figure 3. Rats were approximately 22 weeks (male) or 10 weeks (female) old on receipt. Mice were approximately 8 weeks old on receipt. Animals were quarantined for 7 days. Following the quarantine period, animals were aged onsite and maintained in a pre-exposure housing room prior to the study start. On the first day of the studies, rats were approximately 28–31 weeks (male) or 23 weeks (female) old, and male mice were approximately 33 weeks old. Rats and mice were randomly assigned to one of five exposure groups before the start of the study. Randomization was stratified by body weight that produced similar group mean weights using NTP Provantis software (Instem, Stone, UK).

Before the studies began, five male and five female rats, and five male mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Additionally, the health of the animals was monitored during the studies according to the protocols of the NIEHS/DTT Sentinel Animal Program (Appendix F). All test results were negative.

Groups of 10 male and 10 female rats and 10 male mice were housed individually in reverberation chambers and exposed to whole-body RFR via Code Division Multiple Access (CDMA) (Interim Standard 95 [IS-95], 1,900 MHz) or via Global System for Mobile Communications (GSM) single modulation (900 MHz). Reverberation chambers are described in further detail in Appendix A. Male mice were exposed to 0 (chamber control), 5, 10, or 15 W/kg of radiation via CDMA modulation for 5 days. Male and female rats were exposed to 0 (chamber control), 3, 6, or 9 W/kg of radiation via CDMA modulation for 5 days. Additional groups of male rats were exposed to 0 (chamber control), 3, 6, or 9 W/kg of radiation via GSM modulation for 5 days.

Exposures were scheduled to occur over the course of an 18-hour and 20-minute period each day, from 10:00 to 14:00 and from 15:40 to 06:00 the following day. Exposures did not occur during animal husbandry activities in the morning (06:00 to 10:00) or afternoon (14:00 to 15:40). Throughout the 18-hour and 20-minute period, each exposure group continuously cycled between 10 minutes of RFR exposure (“RFR ON”) and 10 minutes of no exposure (“RFR OFF”), with a total exposure duration of 9 hours and 10 minutes per day (Figure 6). When the system started exposure at 10:00 each day, the stirrers in all four reverberation chambers started moving and continued to move throughout the 18-hour and 20-minute scheduled exposure period, regardless of whether RF was being generated or not. As described in Section 2 and Appendix A, if the chamber doors were opened (e.g., for unplanned activities), the stirrers and RF generation were paused for safety and would resume as scheduled once all doors were securely closed.

Figure 6

Exposure Regimen for Investigative Radiofrequency Radiation Studies

RFR = radiofrequency radiation.

Due to power constraints of the overall system, RFR groups were on opposite interval schedules across the two 10-minute periods of either “RFR ON” or “RFR OFF”. During the first 10-minute period, the high exposure group was exposed, and the low and medium exposure groups were not exposed. During the next 10-minute period, the low and medium exposure groups were exposed, and the high exposure group was not exposed. This pattern continued throughout the 18-hour and 20-minute period. For the purposes of measurements taken as related to exposure status (e.g., video observations, RFR exposure log data), the chamber control group was considered to follow the same pattern as the high exposure group though this group received no RFR exposure. Table 3 demonstrates the exposure schedule using the hour of 10:00–11:00 as an example:

Table 3 Example Exposure Pattern

Time | Chamber Control and High Exposure Groups^a^ | Low and Medium Exposure Groups^b^
10:00–10:10 | RFR ON | RFR OFF
10:10–10:20 | RFR OFF | RFR ON
10:20–10:30 | RFR ON | RFR OFF
10:30–10:40 | RFR OFF | RFR ON
10:40–10:50 | RFR ON | RFR OFF
10:50–11:00 | RFR OFF | RFR ON

RFR = radiofrequency radiation.

^a^ The high exposure group was 9 W/kg for rats and 15 W/kg for mice. For the purpose of measurements taken as related to the status of RFR ON/OFF, the chamber control group followed the exposure pattern of the high exposure group.

^b^ The low and medium exposure groups were 3 and 6 W/kg for rats and 5 and 10 W/kg for mice.

On study day 3, female rats were not exposed for the full duration due to improper closure of the chamber door; thus, female rats were exposed for an additional sixth day. To minimize time between the end of exposure and tissue collection for comet assay, animals were briefly exposed on the day of necropsy up until scheduled removal for necropsy. Subsets of animals were removed during successive “off” exposure periods, with representation across exposure groups during each “off” period. Exposures continued for animals that remained in the chambers until all animals were removed. For mice, individual animals had tissues collected within 8 minutes of euthanasia. For rats, individual animals had tissues collected within 13 minutes of euthanasia. All tissues of interest were collected from all animals within 2 hours and 50 minutes for rats, and within 2 hours and 4 minutes for mice.

Chamber control animals were housed in a reverberation chamber identical to that in which exposed animals were housed, except without an active RFR antenna, and were not exposed to RFR. Furthermore, the chamber shielded the animals from environmental RFR, with the exception of periods when the chamber door was opened for animal care activities. Room control animals were housed in the same room as exposed animals in standard polycarbonate cages and were similarly not purposefully exposed to RFR. Based on measurements over a 24-hour period at the location of the room control animals, the peak measured fields were 56 dB lower than those in the mouse high-power chamber (Figure B-5; Figure B-6) and resulted in specific absorption rate (SAR) levels more than 100,000 times lower in the room control animals than in the exposed animals. Mean SAR levels for the exposures remained within 10% of target levels throughout the studies; summaries of the exposure data are provided in Appendix C. Noise was monitored during all studies, and the minimum, maximum, and mean levels were similar for both average noise and peak noise across all exposure groups in all studies.

Feed and water were available ad libitum. To avoid interference with RFR dosimetry, feed was provided in ceramic (nonmetallic) bowls, and water was delivered in an adapted automatic watering system.^17^ Rats and mice were housed individually during the 5-day studies. Details of the study design and animal maintenance are summarized in Table 4. Information on feed composition and contaminants is provided in Appendix E.

Table 4 Experimental Design and Materials and Methods in the Whole-body Exposure Studies of CDMA- and GSM-modulated Cell Phone Radiofrequency Radiation

Rats | Mice
Testing Facility
Battelle/AmplifyBio⁠⁠^1^ (West Jefferson, Ohio) | Same as rats
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | B6C3F1/N
Animal Source
Envigo (Indianapolis, IN) | Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
CDMA: 59 (males) or 87 (females) days GSM: 38 days (males) | CDMA: 167 days (males)
Average Age When Studies Began
CDMA: 31 (males) or 23 (females) weeks GSM: 28 weeks (males) | CDMA: 33 weeks (males)
Date of First Exposure
CDMA: October 21, 2021 (males) or November 18, 2021 (females) GSM: September 30, 2021 (males) | CDMA: July 22, 2020 (males)
Duration of Exposure
Nine hours and 10 minutes per day, over the course of an 18-hour and 20-minute period, in 10-minute-on, 10-minute-off intervals for 5 (males) or 6 (females) days | Nine hours and 10 minutes per day, over the course of an 18-hour and 20-minute period, in 10-minute-on, 10-minute-off intervals for 5 days
Date of Last Exposure
CDMA: October 26, 2021 (males) or November 24, 2021 (females) GSM: October 5, 2021 (males) | CDMA: July 27, 2020 (males)
Necropsy Dates
CDMA: October 26 (males) or November 24 (females), 2021 GSM: October 5, 2021 (males) | CDMA: July 27, 2020 (males)
Average Age at Necropsy
CDMA: 32 weeks (males) or 24 (females) weeks GSM: 29 weeks (males) | CDMA: 33 weeks (males)
Size of Study Groups
CDMA: 10 males and 10 females GSM: 10 males | CDMA: 10 males
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights | Same as in rats
Animals per Cage
1 | Same as in rats
Method of Animal Identification
Tail tattoo and cage card | Tail marking with permanent pen and cage card
Diet
Irradiated NTP-2000 wafer feed (Zeigler Brothers Inc., Gardners, PA), available ad libitum, ceramic feed bowls | Same as in rats
Water
Tap water (Village of West Jefferson, OH municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI) or via Lixit^®^ in exposure chambers, available ad libitum | Same as in rats
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE), for room control animals Solid polycarbonate (Thoren #7, Thoren Caging Systems, Hazleton, PA) for exposed animals with plexiglass lids | Solid polycarbonate (Lab Products, Inc., Seaford, DE), for room control animals Solid polycarbonate (Thoren #7, Thoren Caging Systems, Hazleton, PA) for exposed animals with filter top lids
Bedding
Irradiated Sani-Chips^®^ (Envigo, Madison, WI) | Same as in rats
Environmental Enrichment
None | Natural crinkled kraft paper (Crink-l’nest™, The Andersons, Maumee, Ohio)
Racks
Stainless steel (Lab Products, Inc., Seaford, DE) for room control animals Custom-designed fiberglass cage racks integrated within the reverberation chambers (Foundation for Research on Information Technologies in Society [IT’IS], Zürich, Switzerland) for exposed animals; reverberation chambers held up to 10 cages | Same as in rats
Rack Filters
Spun-bonded polyester (National Filter Media Corporation, Olive Branch, MS) | Same as in rats
Reverberation Chambers
Fully shielded, stainless-steel chamber equipped with a stainless-steel door to eliminate leakage of RFR signals, RFR excitation antennas, and two rotating stirrers | Same as in rats
Animal Room Environment (Room control animals)
Temperature: 75°F to 78°F Relative humidity: 48% to 53% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 75°F to 76°F Relative humidity: 48% to 53% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Reverberation Chamber Environment (Chamber control and exposed animals)
Temperature: 69°F to 75°F Relative humidity: 47.0% to 60.2% Chamber incandescent light: 12 hours/day Chamber airflow: 0.0 to 1.7 m/sec (adjusted to achieve the target air changes per hour) | Temperature: 69°F to 72°F Relative humidity: 49.0% to 59.5% Chamber incandescent light: 12 hours/day Chamber airflow: 0.0 to 1.6 m/sec (adjusted to achieve the target air changes per hour)
Exposure Level
Time-averaged whole-body SAR levels of 0 (chamber control), 3, 6, or 9 W/kg CDMA- or GSM-modulated cell phone RFR | Time-averaged whole-body SAR levels of 0 (chamber control), 5, 10, or 15 W/kg CDMA-modulated cell phone RFR
Type and Frequency of Observation
Observed twice daily; animals were weighed prior to implantation surgery, initially, and at study termination, and clinical observations were recorded daily. The body temperature data generated by the temperature chips and data loggers were unusable. | Same as in rats
Method of Euthanasia
100% carbon dioxide, followed by exsanguination | 70% carbon dioxide/30% oxygen, followed by exsanguination
Necropsy
Necropsies were performed on all animals | Same as in rats
Genetic Toxicology
At study termination, samples were collected from blood, brain (frontal cortex, hippocampus, cerebellum), heart, and liver for analysis by comet assay. | Same as in rats

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation; GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation; RFR = radiofrequency radiation; SAR = specific absorption rate.

1 These studies were conducted under the NIEHS contract with Battelle Memorial Institute (HHSN273201400015C). The studies were initiated at the Battelle testing facility in West Jefferson, Ohio. On May 1, 2021, the testing facility was transferred to a new company, AmplifyBio. The study was transferred to AmplifyBio as a subcontract under HHS273201400015C. All of the installation and verification activities were conducted while Battelle was the testing facility. For the mouse study, all of the in-life, postmortem, and analytical portions of the study were conducted while Battelle was the testing facility; reporting was conducted under AmplifyBio as the testing facility. The rat studies were conducted under AmplifyBio as the testing facility.

#### 4.2.3.4 Clinical Examinations

Blood was collected immediately prior to study termination from the retroorbital plexus (rats) or sinus (mice) into cryotubes containing cold mincing solution for comet assay. Animals were anesthetized with a carbon dioxide/oxygen mixture and bled in a random order. Necropsies were performed on all animals. After rinsing in cold mincing solution, brain regions (frontal cortex, hippocampus, and cerebellum) and heart tissue were cut into small pieces, and all tissue pieces were flash frozen and stored at −80°C for the comet assay. Liver tissue underwent similar processing except that several small pieces were cut from a small strip of tissue taken from the left lobe of the liver. Samples were stored for a minimum of 3 days before shipment to Integrated Laboratory Systems, LLC, an Inotiv company (Research Triangle Park, NC) for analysis. Information on the comet assay sampling is provided in Appendix D.

Rats and mice were observed twice daily for signs of mortality or moribundity. Clinical observations were recorded initially, daily, and at study termination. Body weights were recorded prior to surgery for data-logger implantation, initially, and at study termination.

#### 4.2.3.5 Video Clinical Observations

To support the planned evaluations, cameras were added to the exposure chambers for select time periods to generate recordings of animals during exposure. As described in Section 2 and Appendix A, each chamber had 10 cage locations in a design of five rows with two cages per row. For each exposure chamber, cameras (five per chamber) were positioned on the chamber door such that one video camera would be directly in front of one cage on each of the five rows when the chamber doors were closed. The room control group similarly had cameras (five per group) positioned directly in front of the cages. Based on video recordings, animals with cameras directly in front of their cage (five animals per exposure group) were evaluated on study days 0, 1, 2, 3, and 4 (mice), or on study days 0 and 4 (rats). Due to the short duration of the studies, cage locations were not rotated throughout the chamber, and the same animals were evaluated at each timepoint. Recorded video was evaluated to gauge whether there were visible changes in animal activity during the first on and off exposure cycles in the morning/light hours (AM ON, AM OFF) and in the first on and off exposure cycles of the evening/dark hours (PM ON, PM OFF). Infrared light was used for illumination during nighttime recording. Table 5 shows the days and times that each video observation was recorded for the four studies.

Table 5 Scheduled Times of Video Recording

| AM ON | | AM OFF | | PM ON | | PM OFF
CDMA Male Mice | 0, 15 W/kg | 5, 10 W/kg | 0, 15 W/kg | 5, 10 W/kg | 0, 15 W/kg | 5, 10 W/kg | 0, 15 W/kg | 5, 10 W/kg
Day 0, 22Jul2020 | 10:00 | 10:30 | 10:10 | 10:40 | 18:00 | 18:10 | 18:10 | 18:20
Day 1, 23Jul2020 | 10:00 | 10:10 | 10:10 | 10:20 | 18:00 | 18:10 | 18:10 | 18:20
Day 2, 24Jul2020 | 10:00 | 10:30 | 10:10 | 10:40 | 18:00 | 18:10 | 18:10 | 18:20
Day 3, 25Jul2020 | 10:00 | 10:10 | 10:10 | 10:20 | 18:40^a^ | 18:30^a^ | 18:30^a^ | 18:40^a^
Day 4, 26Jul2020 | 10:00^b^ | 10:30 | 10:10^b^ | 10:40 | 18:00 | 18:10 | 18:10 | 18:20
CDMA Male Rats | 0, 9 W/kg | 3, 6 W/kg | 0, 9 W/kg | 3, 6 W/kg | 0, 9 W/kg | 3, 6 W/kg | 0, 9 W/kg | 3, 6 W/kg
Day 0, 21Oct2021 | 10:00 | 10:10 | 10:10 | 10:00 | 18:00 | 18:10 | 18:10 | 18:00
Day 4, 25Oct2021 | 10:00 | 10:10 | 10:10 | 10:00 | 18:00 | 18:10 | 18:10 | 18:00
CDMA Female Rats | 0, 9 W/kg | 3, 6 W/kg | 0, 9 W/kg | 3, 6 W/kg | 0, 9 W/kg | 3, 6 W/kg | 0, 9 W/kg | 3, 6 W/kg
Day 0, 18Nov2021 | 10:00 | 10:10 | 10:10 | 10:00 | 18:20^c^ | –^c^ | –^c^ | 18:20^c^
Day 4, 22Nov2021 | 10:00 | 10:10 | 10:10 | 10:00 | 18:00^b^ | 18:10 | 18:10 | 18:00
GSM Male Rats | 0, 9 W/kg | 3, 6 W/kg | 0, 9 W/kg | 3, 6 W/kg | 0, 9 W/kg | 3, 6 W/kg | 0, 9 W/kg | 3, 6 W/kg
Day 0, 30Sept2021 | 10:00 | 10:10 | 10:10 | 10:00 | 18:00 | 18:10 | 18:10 | 18:00
Day 4, 4Oct2021 | 10:00 | 10:10 | 10:10 | 10:00 | 18:00 | 18:10 | 18:10 | 18:00

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation; GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation; AM = morning light hours; PM = evening dark hours.

^a^ Lights were scheduled to turn off at 18:00. On Day 3 (July 25, 2020) of the CDMA male mouse study, lights did not turn off until 18:24; therefore, the PM ON and PM OFF evaluations for all groups were delayed to evaluate the first cycles in the dark period.

^b^ There are three instances in which a video clinical observation was recorded, but the corresponding video files are no longer available due to file corruption. The recorded observations for which videos are not available include a CDMA male mouse (animal 33, day 4, AM ON and AM OFF) and a CDMA female rat (animal 364, day 4, PM ON).

^c^ There was an unscheduled system pause at 18:02 on Day 0 (November 18, 2021) of the CDMA female rat study; therefore, the PM ON and PM OFF video recordings were delayed or unavailable.

Animals were evaluated according to a reaction rating scale of normal, minimal, mild, moderate, and severe (Table 6). Animals were also evaluated over the subsequent full 10-minute “on” period to determine whether there was any change in activity over the 10-minute exposure window; no changes in activity were observed during these observations. Videos used to generate the observations described here are available in the Chemical Effects and Biological Systems (CEBS) database: https://doi.org/10.22427/NIEHS-DATA-NIEHS-RFRB. Videos have been edited to protect privacy by removal of human faces and voices.

Table 6 Reaction Rating Scale for Video Clinical Observations

Score^a^ | Rating Used in Report Narrative | Description
NT | NV | No video available
−1 | Normal | No reaction
0 | Minimal | Slight reaction; ear flinching or flicking within normal limits
1 | Mild | More energetic response than Minimal
2 | Moderate | Exaggerated reaction (e.g., jumps, bites, attacks)
3 | Severe | Rodent freezes, actual muscle contractions

NT = not assigned; NV = no video.

^a^ Numerical score as reported in the individual animal video observations. The individual animal data can be found in Appendix G.

### 4.2.4 Statistical Methods

Statistical methods were chosen based on distributional assumptions. Unless specifically mentioned, all endpoints were tested for a trend across exposure groups, followed by pairwise tests for each exposed group against the chamber control group. Significance of all trend and pairwise tests is determined by a p value of ≤0.05 and is reported at both 0.05 and 0.01 levels. The room control group was analyzed only by a single pairwise comparison to the chamber control group. The room control analysis was kept separate from that of the other exposed groups and was excluded from all trend tests.

#### 4.2.4.1 Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between exposed and control groups in the analysis of continuous variables. Body weight data, which historically have approximately normal distributions, and body temperatures were analyzed with the parametric multiple comparison procedures of Dunnett^20^ and Williams.^21,22^ The Jonckheere test^23^ was used to assess the significance of the exposure-related trends and to determine whether a trend-sensitive test (the Williams’ test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure-related trend (the Dunnett test). Before statistical analysis, outliers identified using the Dixon and Massey test^24^ were examined by NIEHS/DTT personnel, and biologically implausible values (likely due to experimental error) were eliminated from the analysis.

### 4.2.5 Quality Assurance Methods

The 5-day studies were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^25^ In addition, the 5-day study reports were audited retrospectively by an independent quality assurance contractor against study records submitted to the NTP Archives. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NIEHS/DTT scientists, and all comments were resolved or otherwise addressed during the preparation of this report.

### 4.2.6 Genetic Toxicology

The genetic toxicity of whole-body GSM- and CDMA-modulated cell phone RFR was assessed by testing whether the exposure increased DNA damage in cells from the brain (frontal cortex, hippocampus, and cerebellum), liver, heart, and blood of rats and mice following 5 days of exposure. The protocol for these studies and the results are given in Appendix D.

The genetic toxicity studies have evolved from an earlier effort to develop a comprehensive database permitting a critical anticipation of a test article’s carcinogenicity in experimental animals that was based on numerous considerations, including the relationship between the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were developed originally to clarify proposed mechanisms of chemical-induced DNA damage, given the relationship between electrophilicity and mutagenicity,^26^ and the somatic mutation theory of cancer.^27,28^ Not all cancers, however, arise through genotoxic mechanisms.

#### 4.2.6.1 Comet Assay

The alkaline (pH > 13) comet assay,^29^ also known as the single cell gel electrophoresis assay, detects DNA damage in any of a variety of eukaryotic cell types^30-33^; cell division is not required. The type of DNA damage detected includes nicks, adducts, strand breaks, and abasic sites that are converted to DNA strand breaks after treatment of cells in an alkaline (pH > 13) solution. Transient DNA strand breaks generated by the process of DNA excision repair might also be detected. DNA damage caused by crosslinking agents has been detected as a reduction of DNA migration.^34,35^ The fate of the DNA damage detected by the comet assay is varied; most of the damage is rapidly repaired and results in no sustained effect on the tissue, but some damage might result in cell death or be incorrectly processed by repair proteins and lead to a fixed mutation or chromosomal alteration. In these studies, brain (frontal cortex, hippocampus, and cerebellum), liver, heart, and blood samples from rats and mice were tested in the comet assay. The protocol for these studies and the results are given in Appendix D.

## 4.3 Results

### 4.3.1 Data Availability

All study data were evaluated. Data relevant for evaluating findings are presented here. Body temperature data were unusable because of data quality or data collection issues. All study data are available in the CEBS database: https://doi.org/10.22427/NIEHS-DATA-NIEHS-RFRA.^36^

### 4.3.2 Five-day Study in Male Mice Exposed to CDMA-modulated Cell Phone Radiofrequency Radiation

#### 4.3.2.1 Survival and Body Weights

All animals survived until the scheduled termination on study day 5. There were no exposure-related effects on survival or body weights with CDMA-modulated RFR exposure up to 15 W/kg for 5 days in male mice. Body weights of exposed animals were within 5% of the chamber control (0 W/kg) animals and did not reach statistical significance throughout exposure (Table 7). The body weight of the room control group was also within 5% of the chamber control group.

Table 7 Summary of Body Weights of Male Mice in the Five-day Study of CDMA-modulated Radiofrequency Radiation

Study Day | Room Control | 0 W/kg | 5 W/kg | 10 W/kg | 15 W/kg
n | 10 | 10 | 10 | 10 | 10
0^a,b,c^ | 40.8 ± 0.5 | 40.7 ± 0.6 | 40.5 ± 0.6 | 41.3 ± 0.5 | 39.5 ± 0.5
5 | 42.6 ± 0.5 | 41.6 ± 0.8 | 43.0 ± 0.6 | 43.3 ± 0.5 | 42.3 ± 0.6

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

^a^ Data are presented as mean ± standard error. Body weight data are presented in grams.

^b^ Statistical analysis performed by Jonckheere (trend) and Williams or Dunnett (pairwise) tests. Statistical analysis for the room control group compared to the 0 W/kg chamber control group was performed using the t-test. No statistically significant findings were noted at p ≤ 0.05.

^c^ Study day 0 is the day animals were placed on study.

### 4.3.3 Five-day Study in Male Rats Exposed to CDMA-modulated Cell Phone Radiofrequency Radiation

Prior to conducting the rat studies described here in Sections 4.3.3, 4.3.4, and 4.3.5, a number of system modifications and maintenance occurred. These activities are described in more detail in Section 3.4.

#### 4.3.3.1 Survival and Body Weights

All animals survived until the scheduled termination on study day 5. There were no exposure-related effects on survival or body weights with CDMA-modulated RFR exposure up to 9 W/kg for 5 days in male rats. Body weights of exposed animals were within 5% of the chamber control animals and did not reach statistical significance throughout exposure (Table 8). The body weight of the room control group was also within 5% of the chamber control group.

Table 8 Summary of Body Weights of Male Rats in the Five-day Study of CDMA-modulated Radiofrequency Radiation

Study Day | Room Control | 0 W/kg | 3 W/kg | 6 W/kg | 9 W/kg
n | 10 | 10 | 10 | 10 | 10
0^a,b,c^ | 394.2 ± 5.3 | 382.4 ± 5.5 | 384.7 ± 4.8 | 388.1 ± 4.4 | 388.8 ± 4.4
5 | 400.7 ± 6.0 | 401.2 ± 5.1^d^ | 388.2 ± 6.4 | 394.5 ± 3.1 | 387.7 ± 4.7

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

^a^ Data are presented as mean ± standard error. Body weight data are presented in grams.

^b^ Statistical analysis performed by Jonckheere (trend) and Williams or Dunnett (pairwise) tests. Statistical analysis for the room control group compared to the 0 W/kg chamber control group was performed using the t-test. No statistically significant findings were noted at p ≤ 0.05.

^c^ Study day 0 is the day animals were placed on study.

^d^ n = 9. One animal weight in the 0 W/kg chamber control group was excluded from the analysis as an outlier.

### 4.3.4 Five-day Study in Female Rats Exposed to CDMA-modulated Cell Phone Radiofrequency Radiation

#### 4.3.4.1 Survival and Body Weights

All animals survived until the scheduled termination on study day 6. There were no exposure-related effects on survival or body weights with CDMA-modulated RFR exposure for 6 days up to 9 W/kg in female rats. On study day 6, body weights showed a positive trend compared to the chamber control group; however, no pairwise comparisons for exposed groups reached statistical significance, and body weights of the exposed animals were within 10% of the chamber control animals throughout exposure (Table 9). The body weight of the room control group was also within 10% of the chamber control group.

Table 9 Summary of Body Weights of Female Rats in the Five-day Study of CDMA-modulated Radiofrequency Radiation

Study Day | Room Control | 0 W/kg | 3 W/kg | 6 W/kg | 9 W/kg
n | 10 | 10 | 10 | 10 | 10
0^a,b,c^ | 275.6 ± 5.2 | 266.5 ± 6.1 | 267.0 ± 4.5 | 275.1 ± 5.0 | 277.0 ± 3.5
6 | 277.6 ± 4.8 | 264.0 ± 5.0* | 266.5 ± 4.8 | 273.6 ± 5.6 | 279.1 ± 5.1

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

Statistical significance for the 0 W/kg chamber control group indicates a significant trend test; the room control group was excluded from trend test. All comparisons are made to 0 W/kg chamber control.

* Statistically significant at p ≤ 0.05.

^a^ Data are presented as mean ± standard error. Body weight data are presented in grams.

^b^ Statistical analysis performed by Jonckheere (trend) and Williams or Dunnett (pairwise) tests. Statistical analysis for the room control group compared to the 0 W/kg chamber control group was performed using the t-test.

^c^ Study day 0 is the day animals were placed on study.

### 4.3.5 Five-day Study in Male Rats Exposed to GSM-modulated Cell Phone Radiofrequency Radiation

#### 4.3.5.1 Survival and Body Weights

All animals survived until the scheduled termination on study day 5. There were no exposure-related effects on body weights with GSM-modulated RFR exposure up to 9 W/kg for 5 days in male rats. On study day 5, body weights showed a negative trend and a significant decrease in the 6 W/kg group compared to the chamber control group. However, body weights of all exposed groups were within 10% of the chamber control group (Table 10). The body weight of the room control group was also within 5% of the chamber control group.

Table 10 Summary of Body Weights of Male Rats in the Five-day Study of GSM-modulated Radiofrequency Radiation

Study Day | Room Control | 0 W/kg | 3 W/kg | 6 W/kg | 9 W/kg
n | 10 | 10 | 10 | 10 | 10
0^a,b,c^ | 374.2 ± 4.7 | 377.7 ± 5.2 | 377.4 ± 5.0 | 360.2 ± 7.7 | 373.2 ± 3.4
5 | 379.0 ± 4.0 | 382.5 ± 3.7* | 381.9 ± 5.5 | 352.7 ± 13.5* | 368.2 ± 5.0

GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation.

Statistical significance for an exposed group indicates a significant pairwise test compared to the 0 W/kg chamber control group. Statistical significance for the 0 W/kg chamber control group indicates a significant trend test; the room control group was excluded from trend test. All comparisons are made to 0 W/kg chamber control group.

* Statistically significant at p ≤ 0.05.

^a^ Data are presented as mean ± standard error. Body weight data are presented in grams.

^b^ Statistical analysis performed by Jonckheere (trend) and Williams or Dunnett (pairwise) tests. Statistical analysis for the room control group compared to the 0 W/kg chamber control group was performed using the t-test.

^c^ Study day 0 is the day animals were placed on study.

### 4.3.6 Video Clinical Observations

Another factor in assessing the use of the exposure system for conducting toxicological research was to understand the extent to which animals were aware of or stressed by the RF signal itself, the GSM-associated noise, or movement of stirrers in the chambers. Video cameras were placed within the exposure chambers to capture video footage of animals during exposure. Recorded video was evaluated during the first RFR ON and first RFR OFF cycle during the morning/light hours (AM ON, AM OFF) and during the first RFR ON and RFR OFF cycle during the evening dark hours (PM ON, PM OFF). Across nearly all animals and all time points evaluated, there were no consistent, exposure-related, and visible changes in activity that would indicate the animals were aware of or stressed about the initiation or cessation of exposure in the chambers.

A summary of the frequency of normal video clinical observations in mice and rats is presented in Table 11 and Table 12 below. The tables combine observations across exposure groups within each study.

Table 11 Frequency of “Normal” (i.e., −1 Reaction Score) Recordings in Male Mice in the Five-day Study of CDMA-modulated Radiofrequency Radiation^a^

| Day 0 | Day 1 | Day 2 | Day 3 | Day 4 | Total Across Days (%)
AM ON | 12/13^b^ | 23/23 | 20/20 | 25/25 | 23/23 | 103/104 (99%)
AM OFF | 13/13 | 23/23 | 20/20 | 25/25 | 23/23 | 104/104 (100%)
PM ON | 23/23 | 18/18 | 19/19 | 23/23 | 19/19 | 102/102 (100%)
PM OFF | 23/23 | 18/18 | 19/19 | 23/23 | 19/19 | 102/102 (100%)

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation; AM = morning light hours; PM = evening dark hours.

^a^ Reported observations in this table are combined across all five exposure groups. All observations not recorded as “normal” are described in footnotes. A subset of animals (goal of five animals per exposure group) was monitored for each period. Video observations were sometimes unavailable for all animals (e.g., animal was not visible in video or infrared illumination was inadequate for video capture).

^b^ One animal (#29, 5 W/kg) had a recording of 0 on Day 0 at the first AM ON period.

Table 12 Frequency of “Normal” (i.e., −1 Reaction Score) Recordings in Male and Female Rats in the Five-day Studies of CDMA- and GSM-modulated Radiofrequency Radiation^a^

| Day 0 | Day 4 | Total Across Days (%)
CDMA Male Rats
AM ON | 21/23^b^ | 22/22 | 43/45 (96%)
AM OFF | 23/23 | 22/22 | 45/45 (100%)
PM ON | 22/22 | 21/21 | 43/43 (100%)
PM OFF | 22/22 | 21/21 | 43/43 (100%)
CDMA Female Rats
AM ON | 25/25 | 24/24 | 49/49 (100%)
AM OFF | 25/25 | 24/24 | 49/49 (100%)
PM ON | 12/12^c^ | 24/25^d^ | 36/37 (97%)
PM OFF | 12/12^c^ | 25/25 | 37/37 (100%)
GSM Male Rats
AM ON | 16/17^e^ | 22/22 | 38/39 (97%)
AM OFF | 17/17 | 22/22 | 39/39 (100%)
PM ON | 21/21 | 22/22 | 43/43 (100%)
PM OFF | 20/21^f^ | 22/22 | 42/43 (98%)

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation; GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation; AM = morning light hours; PM = evening dark hours.

^a^ Reported observations in this table are combined across all five exposure groups. All observations not recorded as “normal” are described in footnotes. A subset of animals (goal of five animals per exposure group) was monitored for each period. Video observations were sometimes unavailable for all animals (e.g., animal was not visible in video or infrared illumination was inadequate for video capture).

^b^ One animal (#300, 9 W/kg CDMA male rat) had a recording of 0, and one animal (#297; a second 9 W/kg CDMA male rat) had a recording of 1 on Day 0 in the AM ON period.

^c^ For CDMA female rats, video cameras did not capture the entire RFR ON and RFR OFF cycles in the PM period on Day 0. As a result, video observations are unavailable for the first PM ON for the 3 W/kg group, the 6 W/kg group, and some room control animals. Video observations are also unavailable for the first PM OFF transition for the 0 W/kg chamber control group, the 9 W/kg group, and some room control animals.

^d^ One animal (#355, room control CDMA female rat) had a recording of 0 on Day 4 at the first PM ON period.

^e^ One animal (#197, 9 W/kg GSM male rat) had a recording of 1 on Day 0 at the first AM ON period.

^f^ One animal (#182, 6 W/kg GSM male rat) had a recording of 1 on Day 0 at the first PM OFF period.

For the CDMA mouse study, all video clinical observations were recorded as normal, with the exception of one animal in the 5 W/kg group that was recorded as having a minimal response on study day 0 during the first AM ON evaluation (Table 11). A minimal response was considered a slight reaction with ear flinching or flicking within normal rodent activity limits.

For video clinical observations in the rat studies, most recordings were within normal limits (Table 12). In a few instances, animals were observed to show some changes in activity. Two CDMA male rats in the 9 W/kg group during the first AM ON evaluation were recorded as having a minimal or mild response; specifically, one 9 W/kg CDMA male rat was recorded as having a minimal response, and one 9 W/kg CDMA male rat was recorded as having a mild response. A mild response was considered more energetic than the minimal response.

Video clinical observations showed that all CDMA female rats in the chambers had normal responses at the time points evaluated (Table 12). Two GSM male rats (one each in the 6 and 9 W/kg groups) were recorded as having responses greater than normal during the exposure signal transitions on study day 0. One 9 W/kg GSM male rat during the first AM ON evaluation was recorded as having a mild response, and one 6 W/kg GSM male rat during the first PM OFF evaluation was recorded as having a mild response.

In addition to evaluating animals at AM ON, AM OFF, PM ON, and PM OFF, animals were evaluated over a full 10-minute “on” period during the morning and evening exposures to determine whether there was any change in activity over the exposure period. No changes in activity were observed during these observations.

### 4.3.7 Genetic Toxicology

DNA damage from exposure to RFR was assessed in frontal cortex, hippocampus, cerebellum, liver, blood, and heart cell samples from male mice and male and female rats using the comet assay (Table D-1, Table D-2, Table D-3, and Table D-4). For CDMA male mice, there were no significant increases in DNA damage, measured as the percent tail DNA, in cells sampled from the three brain regions, blood, and heart tissue; there was a significant trend test for the percent tail DNA in liver cells that is of uncertain biological significance. For CDMA male and CDMA female rats, no significant increases in the percent tail DNA were observed for any tissue. For GSM male rats, there were no significant increases in DNA damage, measured as the percent tail DNA, in cells sampled from frontal cortex, cerebellum, liver, blood, or heart tissue; there was a significant trend test for the percent tail DNA in hippocampal cells that is of uncertain biological significance.

The percent tail DNA for room control animals and chamber control animals was not significantly different for 20 of the 24 tissues examined in the 5-day studies. For CDMA male mice, the percent tail DNA was lower in the frontal cortex and higher in the heart in the room control group compared to the chamber control group. For GSM male rats and CDMA female rats, the percent tail DNA in heart tissue was lower in the room control group compared to the chamber control group. For these four instances in which significant differences in the percent tail DNA were detected between the two control groups, the differences did not reach twofold (1.5–1.6-fold) except for the frontal cortex cells in CDMA male mice, which showed a twofold difference in the chamber control group over the room control that may be considered biologically relevant. Notably, negative results were observed in the dose-response studies for each of these four tissues (i.e., heart and frontal cortex in CDMA male mice and heart in GSM male rats and CDMA female rats).

## 4.4 Summary

Five-day studies were conducted in male mice or male or female rats to evaluate the effect of exposure to the same CDMA- or GSM-modulated RF signals used in the previous NTP studies. Video from the cameras in the exposure chambers demonstrated no consistent, exposure-related, and visible changes in activity in either rats or mice the first time the exposure system was activated, at subsequent system on/off transitions, or during the periods of exposure. There were no exposure-related effects on survival or body weights following exposure to RFR for 5 days. There was no increase in DNA damage following exposure to RFR for 5 days, as measured using the comet assay, in brain cells (frontal cortex, hippocampus, and cerebellum), or in liver, heart, or blood cells of mice and rats. Body temperature measurements were collected during the studies using two different devices; however, the data were unusable.