# 3 System Verification and Operations

## 3.1 System Verification

To verify the parameters of radiofrequency radiation (RFR) exposures recorded by the data-capture component of the exposure system, technical experts from the National Institute of Standards and Technology (NIST) conducted an independent verification of the system following installation and initial testing of the exposure system by the Foundation for Research on Information Technologies in Society (IT’IS) at the testing facility. NIST specifically evaluated RFR exposure fields, chamber characteristics (field uniformity), and signal quality. Full details of the procedures for measurements and calculations are available in Appendix B. The radiofrequency (RF) signals generated by the exposure system were within the estimated uncertainty bounds, indicating that the chamber fields measured by NIST agreed with the measurements provided by the exposure system’s integrated probes. The magnitude of field variation throughout the volume of the chambers was also consistent with values reported for the chambers in the previous National Toxicology Program (NTP) studies. The quality of the modulated signals was found to be acceptable with regard to distortion and harmonic content. Overall, the NIST evaluation confirmed that the exposure system was operating correctly and RFR exposures were within specifications. These activities were conducted prior to the initiation of any animal studies.

## 3.2 Ambient Field Measurements

Additionally, NIST measured ambient levels of RFR at various locations in the facility to assess any potential differences at different locations across the facility. Measurements were taken at four separate locations within the testing facility, including the room housing the reverberation chambers and three other locations that represented a large geographic distribution throughout the facility. Data demonstrated that there were no marked differences in exposures among the sites evaluated across the facility.

## 3.3 System Qualification

Following installation of the exposure system and independent evaluation by NIST, the testing facility conducted a system qualification to ensure the accuracy and functionality of the system for the intended use. The qualification procedures were executed prior to initiation of the mouse study, and again after system repair prior to the rat studies being conducted. Qualification procedures were conducted with facility Wi-Fi enabled and with Wi-Fi disabled. Qualification included simulations to assess the following functionality:

- Initiate a test session using Global System for Mobile Communications (GSM) modulation and confirm program settings for exposure.
- Initiate a test session using Code Division Multiple Access (CDMA) modulation and confirm program settings for exposure.
- Confirm generation and readability of exposure log files from the IT’IS Evaluation Software.
- Confirm functionality of the emergency safety buttons and emergency door switch.
- Confirm functionality of all environmental sensors (temperature, humidity, airflow, noise, vibration, light), including testing of the alarm and abort functions by forcing parameters out of specification (min or max thresholds) for each parameter.
- Run a full simulated study similar to that planned for the rat exposures, including programming of animal body weights, reviewing the exposure configuration with the correct modulation, initiating exposure, stopping/pausing exposure, and generation and reading of the exposure log from the IT’IS Evaluation Software.

## 3.4 System Modifications for Rat Exposure Studies

This section describes system modifications and maintenance that were required after the system described above was installed and used to conduct the mouse study (the mouse study is described below in Section 4.2). These unanticipated modifications were required to conduct the rat studies detailed in Section 4.2. The section below was written based on correspondence between the National Institute of Environmental Health Sciences Division of Translational Toxicology (NIEHS/DTT), the testing facility, and IT’IS. Events are described in chronological order between August 2020 and November 2021 and are depicted in Figure 3.

Figure 3

Timeline Diagram

### 3.4.1 Fabrication of Replacement Cage Lids

The in-life portion of the mouse study was completed in July 2020 (see Section 4.2 for study schedule). The in-life portion of the rat studies were originally scheduled to begin in early August 2020. During the acclimation period, prior to the start of exposure, it was discovered that the rats were able to chew through the cage filter tops and escape their cage units. This was not observed in the mouse study because the height of the cage units did not allow mice to access the filter tops. When the issue was discovered, the study animals were moved back to traditional housing. The testing facility, in consultation with NIEHS/DTT and IT’IS developed a plexiglass cage lid prototype. This cage lid prototype was evaluated for compatibility with the exposure system by measuring temperature and oxygen levels within the cage units during an hour of RF generation. Following testing with acceptable results, the testing facility fabricated plexiglass cage lid replacements for the 40 cages needed for the rat studies. Figure 4 shows the original filter tops used in the mouse study and the replacement plexiglass lids used in the rat studies.

Figure 4

Cage Lids

Images of (A) the original filter tops used in the mouse study, and (B, C) the replacement plexiglass lids used in the rat studies.

### 3.4.2 System Maintenance

Following fabrication of new cage lids, the rat studies were rescheduled to begin in mid-August 2020. Upon restarting the first rat study, the exposure system was found to abort the scheduled exposure due to excursion of the electric field (E-field) probe measurements from the required specification. This issue resulted in animals often receiving less than the required exposure of 9 hours and 10 minutes per day (over the scheduled 18-hour and 20-minute period). A stirrer in the medium-exposure chamber (Chamber 2) also stopped working at the same time. After a review of the system files and exposure logs, it was originally hypothesized that the two events were related (i.e., the stirrer would malfunction and cause the E-field probe measurement to be out of specification), which in turn would cause the system to abort. In an attempt to resolve this issue, the motor for the stirrer in Chamber 2 was replaced at the end of August 2020. Following the motor replacement, the system functioned well for a couple of days before the stirrer malfunction and E-field measurement issues recurred.

Throughout September 2020, IT’IS provided remote support to evaluate options for resolving the stirrer malfunction. One option that IT’IS suggested would have required manual (e.g., power the system off and restart) operation of the exposure system by the testing facility. Another option required the development of automatic procedures that could be used when the stirrer malfunction occurred. The manual options were not preferred as they could not be employed during the night hours in which animals were exposed.

By mid-November 2020, a revised stirrer control program had been implemented. To allow the stirrers to be restarted independently and automatically, control of the stirrers was moved into a separate application from the main application that controlled the remainder of the exposure system. The main application controlled the stirrer application via a protocol that defined stirrer speed and acceleration. The main application monitored the speed of each stirrer. If the specified speed was out of specification by more than 50% and for longer than 1 minute, then an error event was triggered.

When an error event was triggered for a stirrer, the stirrer application stopped all stirrers and sent an error message to the main application, which placed the system in pause mode. When the stirrer application sent an error to the main application, the main application waited 5 seconds and then restarted the stirrer application from off-mode. When the stirrer application came back online, it received information via the established protocol with the main application and restarted the stirrers at the specified speed and acceleration they were in before the error occurred.

In the September–November 2020 time period, one of the chamber controllers was replaced and adjustments were made to address the E-field measurement issue. For the E-field measurements, IT’IS expanded the sampling window used to determine whether the probe measurement was within specification. By expanding the window, the effects of minor excursions on the overall mean were reduced and better aligned with the intention of the specification. This modification resolved the issue by preventing minor excursions from affecting the system aborts.

During requalification testing, in late November–early December 2020, some additional software updates and program modifications were required to ensure compatibility with all the new hardware and software. By mid-December 2020, the revised system had been requalified (without animals) and was available for further RFR exposure evaluation.

### 3.4.3 Cage Grommet Modification

After the above system maintenance was completed, a final qualification study (with rats) was performed in January 2021 prior to rescheduling the 5-day investigative rat studies. During the January 2021 qualification, rats in all exposure chambers were observed to lose weight (including in the chamber control chamber). The first attempt to conduct the 5-day investigative studies (fall of 2020) with larger rats (>400 g) also provided indications (e.g., weight loss and animals observed pawing at the lixits) that larger rats had some water access issues in the chamber housing.

To better understand the observed weight loss and refine the study design (e.g., potentially extend chamber acclimation), an experiment was performed in February 2021. This experiment used rats of different weight ranges (250 g and >400 g) and included a period when animals were housed in normal caging for 1 week (study day 0–7) and then moved into the chamber caging on study day 7 for 2 weeks to assess changes in body weight and clinical observations. No RFR exposure was used in this experiment. The body weight results after animals were moved into the chamber housing recapitulated the weight loss findings from the January 2021 qualification study (Table 1). All animals in the >400 g chamber housing group lost weight starting on study day 9, and the magnitude of weight loss was higher than observed in the smaller rats. Weight loss in the 200 g chamber housing group was variable across study days and relatively minor.

Table 1 Body Weights of Male Rats in Different Housing Conditions

Study Day | 200 g Rats Chamber Housing^a,b^ | 200 g Rats Room Control^a^ | 400 g Rats Chamber Housing^a,b^ | 400 g Rats Room Control^a^
n | 20 | 5 | 20 | 5
2 | 232.6 ± 1.3^c^ | 234.7 ± 4.0 | 404.1 ± 2.8 | 408.8 ± 15.9
3 | 238.7 ± 2.0^c^ | 245.0 ± 2.1 | 415.6 ± 3.2 | 419.6 ± 18.1
4 | 242.3 ± 2.7 | 251.7 ± 1.8 | 424.0 ± 2.7 | 422.9 ± 20.0
7 | 257.8 ± 1.9 | 263.2 ± 2.2 | 433.5 ± 1.9 | 437.4 ± 13.4
8 | 264.8 ± 1.6 | 269.4 ± 1.5 | 439.7 ± 1.8 | 441.0 ± 14.9
9 | 261.7 ± 3.1 | 267.9 ± 2.5 | 415.1 ± 1.8 | 434.4 ± 12.5
10 | 268.8 ± 2.4^d^ | 272.9 ± 2.2 | 404.4 ± 2.4 | 442.8 ± 15.1
11 | 271.7 ± 2.4^d^ | 275.5 ± 2.3 | 396.3 ± 4.3 | 445.7 ± 14.8

^a^ Data are presented as mean ± standard error. Body weight data are presented in grams.

^b^ For study days 2–7, body weights were collected while all animals were in traditional housing. On study day 7, animals were moved into the cages within the radiofrequency radiation exposure chambers (no radiofrequency radiation was generated).

^c^ n = 18. Two animal weights in the 200 g chamber housing group were excluded from the analysis as outliers.

^d^ n = 19. One animal weight in the 200 g chamber housing group was excluded from the analysis as an outlier.

Following observations of the larger rats pawing at the lixits, veterinary staff and technicians suspected an issue with access to the watering system. To help confirm their suspicions, approximately half of the >400 g rats in chamber housing were provided hydrogels to supplement water intake. All animals that were provided hydrogels finished them within the first day and, with continued supplementation, started to gain weight. In light of this response, the study team was confident the weight loss issue was related to water access in the chamber housing. Animal technicians hypothesized that the larger animals were unable to maneuver into the correct position to activate the lixit with their lower jaw due to the position/opening size and their head sizes.

Drawing on the findings from the February 2021 experiment, the testing facility began working with IT’IS to evaluate options to improve water access for the larger rats. Between March and June 2021 the testing facility, IT’IS, and NIEHS/DTT evaluated the cage and water access parameters, taking into consideration differences between the exposure system used in the previous NTP studies and the exposure system designed for the current NIEHS/DTT studies. Figure 5 illustrates the construction of the water system including the cage grommets, lixits, and choke tubes. There were several adjustable parameters, and ultimately it was decided that new grommets with a wider opening would be the most appropriate modification to allow better access for the larger rats.

Figure 5

Water System Components

(A) The cage grommet which is an opening in the cage allowing access to the lixit. (B) The metal lixit within the choke tube that shields the lixit from radiofrequency radiation (RFR) exposure (also shown in Appendix A, Section A.11.5).

New grommets were custom manufactured and evaluated by IT’IS to ensure they were appropriate for use in an RF field. Following confirmation of acceptability within the RF field, IT’IS provided new grommets to the testing facility for testing with the large rats. The testing facility conducted two experiments (without exposure) between June and August 2021 to test the new grommets in modified cages. The experiments were designed to investigate water accessibility for the larger rats with the new grommets by confirming animals did not experience body weight loss after being moved into the chambers in modified cages. The first small experiment using n = 2 rats looked promising and supported production and testing of a larger batch of new grommets/modified cages. Within the larger experiment (n = 20 per group, mean body weight >500 g) in August 2021 groups of rats housed in the modified cages were compared to rats housed in standard caging over the course of 2 weeks (Table 2). Both groups gained weight over the course of the experiment, with animals in the modified cages gaining slightly more weight than the room control animals. Following successful resolution of the water access issue, the 5-day investigative rat studies were rescheduled.

Table 2 Body Weights of Male Rats in Different Housing Conditions Following Cage Grommet Modifications

Study Day | 500 g Rats Chamber Housing^a,b^ | 500 g Rats Room Control^a^
n | 20 | 20
−4 | 515.8 ± 11.6 | 515.4 ± 11.6
1 | 508.2 ± 10.5 | 497.3 ± 13.9
5 | 524.2 ± 11.1 | 516.9 ± 13.2
8 | 522.5 ± 10.7 | 518.5 ± 12.8
12 | 532.7 ± 10.5 | 524.5 ± 11.9
15 | 531.2 ± 10.3 | 525.2 ± 11.4

^a^ Data are presented as mean ± standard error. Body weight data are presented in grams.

^b^ For study day −4, body weights were collected while all animals were in traditional housing. On study day 0, animals in the 500 g chamber housing group were moved into the cages within the radiofrequency radiation exposure chambers (no radiofrequency radiation was generated).

The rat studies were reinitiated and conducted between September and November 2021. Throughout the rat studies, additional technical challenges were encountered which required the system to be remotely reset by IT’IS prior to initiating each programmed exposure. Without coordinating this remote system reset, the system would abort exposure due to an error related to the EASY4 system monitoring. While these challenges did not significantly affect the overall schedule of studies conducted, it added a layer of complexity to scheduling and coordination. The root cause of the EASY4 system abort in this case was never identified.

## 3.5 Summary

The comprehensive verification and subsequent modifications of the RFR exposure system were crucial to ensure its accurate, reliable, and safe operation for animal studies. Following installation of the exposure system, experts from NIST independently confirmed the system's internal probe measurement of RFR, field uniformity, and signal quality. Following this verification, the testing facility developed and performed qualification procedures to confirm the system's functionality. These procedures included testing the system's performance under different modulation schemes (GSM and CDMA), verifying the environmental controls (temperature, humidity, airflow, noise, vibration, light), and confirming the proper functioning of emergency systems and safety protocols.

Unexpected technical issues were encountered requiring system modifications. Key modifications included designing new plexiglass cage lids to prevent rats from escaping, resolving stirrer and E-field probe issues through hardware and software updates, and improving water access for larger rats by modifying cage grommets. These detailed measures were essential to ensuring the integrity and reliability of the RFR exposure system and to facilitating accurate and dependable animal studies while maintaining high standards of animal care and safety.