# 2 Chamber Design, Exposure Generation, and Monitoring

## 2.1 Introduction

The radiofrequency radiation (RFR) exposure system was designed to produce exposure conditions identical to those utilized in the previous National Toxicology Program (NTP) studies. The reverberation chamber-based exposure design included an automatic control system with exposure and environmental condition monitoring and logging. Each reverberation chamber was a resonant box in which the resonances and field structure were continuously modified under the influence of metallic stirrers, while shielding the outside environment from the fields inside the chambers and preventing external RFR exposure into the chamber. The RFR exposures were generated and monitored by a computer-controlled system that comprised a radiofrequency (RF) source, signal amplifiers, and a data acquisition system. Each reverberation chamber was equipped with sensors that enabled the computer control system to monitor and record the exposure and environmental conditions. Like the large-scale system used in the previous NTP studies, the small-scale RFR exposure system included four chambers, each capable of delivering a different power level of RFR, but it was designed on a smaller scale to accommodate a smaller number of animals with a smaller facility footprint.

The exposure system was designed, constructed, and tested at the Foundation for Research on Information Technologies in Society (IT’IS) in Zürich, Switzerland. The system was then disassembled, shipped to the testing facility in West Jefferson, Ohio, reassembled, and installed before final system verification and qualification could be conducted.

## 2.2 Chamber Design

The final chamber design, including supporting information, tables, and figures are shown in Appendix A, Section A.3. A reverberation chamber exposure system was used for the studies for the primary benefit that controlled exposures can be achieved in unrestrained animals (e.g., rats and mice).

Each reverberation chamber (Figure 1) was designed to house 10 cages with one animal per cage in Thoren #7 cages (Hazleton, PA) with a cage floor area of 474 cm^2^. Based on the homogeneity results of previous analyses that modeled the specific absorption rate (SAR) distribution of RFR across the whole body, rats were exposed at a frequency of 900 MHz, and mice were exposed at 1,900 MHz.^17^ The chambers were constructed of stainless steel with fully welded seams to ensure no RF leakage. Additionally, a twin finger stock approach was used on the chamber doors to achieve the required shielding effectiveness, and a latch was used to secure the door in the closed configuration. Power and other electrical connections were fully shielded or filtered. Power was passed through a Mains filter (Schaffner, Luterbach, Switzerland) with suitable attenuation characteristics inserted into the chamber wall with a stainless-steel box on the inside of the chamber and a plastic box for protection on the outside. Each chamber contained two mode stirrers, one horizontal on the ceiling and one vertical on the rear wall; the stirred volume was 0.29 m^3^ and the chamber volume was 2.31 m^3^, corresponding to 12.5% stirred volume.

Figure 1

Internal View of a Reverberation Chamber

### 2.2.1 Stirrers

The stirrers were designed to have large reflecting surfaces, whereby the angles between surfaces and angles of rotation with respect to the main axis ensured no radial symmetry. The stirrers function like fans, rotating about their axes; however, the stirrers reflect the electromagnetic fields instead of moving air around with “blades.” By avoiding symmetry, the scattered field has higher complexity over each rotation, leading to higher homogeneity of the field within the chamber volume. Each stirrer was driven by a motor and gear box that were mounted via rubber isolating mounts, which allowed some movement and decreased transmitted vibration. Supporting information, tables, and figures are shown in Appendix A, Section A.3.2.

While reviewing videos captured during exposure (see Section 4.2.3.5), it was noted that the stirrer on the back wall of the control chamber (Chamber 4) did not move throughout the four experiments (male mouse CDMA, male rat CDMA, female rat CDMA, male rat GSM). It is hypothesized that at an unidentified point in time after chamber characterization and before the start of the mouse experiment, the coupling between the motor and the stirrer came loose. As the stirrers were stopped during the animal care and observation periods for safety reasons, the issue was not identified by staff. Furthermore, while a problem with the motor or controller would have been detected by the control software, a mechanical issue like that hypothesized here would not have been detected.

### 2.2.2 Airflow and Vents

The temperature and humidity in the chambers were not independently controlled but relied on the control and sufficiency of airflow from the exposure room. Air was blown into and extracted from the chamber by means of speed-controlled fans (Sanyo Denki, Tokyo, Japan). The fans were chosen to ensure that higher-than-required airflows could be achieved, and the correct number of air changes per hour was obtained by reducing the fan speed as required. By reducing the fan speed, the noise was kept to a minimum. The walls of the chamber had two integrated honeycomb vents, one located at the rear at the left and the other at the top front right. The inlet manifold had an air filter consisting of a coarse mesh material in front of the fans, followed by the honeycomb vents, which prevented the RF signal from propagating out of the chamber, while allowing the air to pass through. A sensor box was attached to the outlet manifold mounted to the top exterior of the chamber, with sensors projecting into the airflow to measure temperature, humidity, airflow, light, and noise. Sensor functionality is described in more detail below. Supporting information, tables, and figures are shown in Appendix A, Section A.3.3.

### 2.2.3 Lighting System

The chambers were equipped with halogen-based incandescent and light emitting diode (LED) lighting. The incandescent light fixtures were placed in the rear of the chamber. Incandescent lighting was used in the previous NTP studies, and the halogen incandescent bulbs used in this study were very similar. The chambers were also equipped with LED corner panels, 1.2 m in length, which were installed in both front corners of the chamber. While the chamber LED lights were not powered on during the animal studies described in this report, the LED lights were used during the system verification activities as the significantly higher light output allowed the LED lighting to be used as inspection lighting The LEDs were operated on 24 V direct current (DC) delivered by a small power supply installed inside the internal electrical filter box. A switch on the box allowed toggling between LED and incandescent lighting in each chamber. The chamber lights were connected to the main facility lighting circuit and hence the on/off timing was fully controlled by the facility, providing a controlled 12-hour light/dark cycle. Supporting information, tables, and figures are shown in Appendix A, Section 3.5.

### 2.2.4 Water System, Caging, and Cage Racks

Cages, cage racks, and watering systems for standard laboratory use contain metallic elements that can alter the exposure of the animals or introduce potential confounding factors. Because cage racks and the drinking water delivery system are contained inside the chambers during exposure periods, it was critical that these components be constructed of durable materials with minimal impact on the RF fields generated in the chamber. Because metal is incompatible with RFR and can interfere with RF signals, all metallic cage rack components (with exception of small rivets), cage lids, feed dispensers, and cage grommets had to be eliminated. Hence, custom engineering was required to overcome the challenges related to potential RFR exposure-altering aspects of all the components used to house the animals during the studies.

Water access through water bottles or a standard automatic watering system in the reverberation chambers would introduce the potential for enhanced exposure fields by metallic sipper tubes (lixits) or excessive, dose-dependent heating of stored water through the absorption of RFR energy by the water. The absorption of RFR energy by water could result in significant heating of the drinking water, thereby decreasing water palatability and increasing the required RF power to achieve the desired exposure field strength, potentially to the extent that the exposure levels could not be met. To overcome these challenges, adaptations were made to an automatic watering system so that the delivery of drinking water to the animals would not interfere with RFR dosimetry. The water system was constructed from stainless steel to ensure no dose-dependent energy absorption occurred in the water (avoiding exposure-dependent water temperature) or in structures around the lixits, preventing the formation of enhanced fields that could lead to excessive increases in the SAR in the animals while drinking.

Two individual automatic water systems were installed: one for use at 900 MHz for rats and the other for use at 1,900 MHz for mice. The lixit (SE Lab Group, Hickory, NC) openings were at 57.5 mm and 82.5 mm above the bottoms of the cages for mice and rats, respectively. The cage grommets were ceramic and custom manufactured for use in these studies. Modifications to the cage grommets used in the rat studies are shown in Section 3.4.3. Two types of cages were provided for use in these studies. Cages for rats had grommets positioned correctly for operation at 900 MHz, and cages for mice had grommets positioned correctly for operation at 1,900 MHz. Supporting information regarding the water system is provided below under Section 2.5.4.

Both rats and mice were housed in reverberation chambers in Thoren #7 single rat-size cages with dimensions 308 × 222 × 222 mm (L × W × H) and a 474 cm^2^ cage floor area. The cage rack was mounted internally, and each cage could be removed for cleaning. The cages with lids slid into the cage racks to a depth set by adjustable stops, ensuring that the grommet and lixit were aligned. Below the lixits and above the next cage was a U-shaped channel to catch water from any leaking lixits and ensure that the cage would not become flooded. Supporting information, tables, and figures are shown in Appendix A, Sections A.3.6 and A.3.10.

### 2.2.5 Video Cameras

Because of the closed design of the chambers and the desire to observe animals during exposure, the chambers were designed to incorporate video cameras. The infrared (IR) camera selected was the Transcend DrivePro Body 1080p camera. The cameras were placed within Faraday boxes to provide shielding to prevent errors or artifacts during operation in the RF field environment of the reverberation chamber. Furthermore, because of the all-metal construction, there was no absorption of energy, and the incident field was scattered. As the reverberation chamber environment was designed to give maximum scattering of the fields, the camera had no impact on the exposures provided. The cameras were placed more than half a wavelength from the nearest cage, and because the cameras were mounted on the metallic door, their presence had no impact on the RF field. These cameras were selected because they had a built-in recorder and did not need to transmit live data to an external device, which would have introduced additional challenges. Supporting information, tables, and figures are shown in Appendix A, Section A.12.

### 2.2.6 Safety

The system included multiple safety features to alert staff about the state of the system and avoid unwanted shutdowns or breaks in exposure. Each chamber was equipped with a set of warning lights that indicated the exposure status, and all amplifiers were connected to the chamber door interlock switches. In the event the door was opened during exposure, the switches would place the system in a safe state by turning off the power to the RF amplifiers. The software would then subsequently turn off all other elements of the RF generation signal chain. This functionality was hardwired; therefore, a software element was not required for the system to be placed into a safe state. In addition, emergency stop buttons installed in the exposure room and close to the control and amplifier racks allowed the RF power to be immediately removed from the system.

The monitoring software tracked and recorded all of the events described above in an exposure log; a summary of the exposure data during the animal studies is included in Appendix C. In the event of a power loss or software crash on the control computer, the system was placed in a safe state for the welfare of the animals. If the exposure field exceeded a given threshold above the target exposure level, the exposure was aborted. Supporting information, tables, and figures are shown in Appendix A, Section A.4.

## 2.3 Signal Generation and Amplification

### 2.3.1 Signal Generator

The signal generator (SMBV-100A, Rhode & Schwarz, Germany) chosen was capable of generating the types of signals used in the previous NTP RFR studies.^12,13^ The signal generator was also extremely flexible and could generate modulations with base bandwidths of up to 120 MHz and carrier frequencies of up to 3.2 GHz, and the software allowed any arbitrary complex modulation (32 Mb) to be generated. This signal generator is capable of providing modulation encompassing 2G, 3G, and 4G signals as well as Wi-Fi.

### 2.3.2 Modulation

Two different modulation and access schemes were utilized during these experiments, namely, those associated with the Global System for Mobile Communications (GSM) standard offset quadrature phase-shift keying (OQPSK) modulation with time division multiple access (TDMA) and the Interim Standard 95 (IS-95) standard using spread spectrum modulation with Code Division Multiple Access (CDMA). Throughout this report, these two modulations are referred to as GSM and CDMA when discussing the results from animals exposed to GSM- or CDMA-modulated RFR exposure.

GSM Modulation: The signal characteristics from GSM mobile handsets are mainly determined by the multiple access method applied. GSM supports both frequency division multiple access (FDMA) and TDMA. For FDMA, the GSM band is divided into 200 kHz-wide channels. Complementing FDMA, a TDMA mechanism enables up to eight time slots (voice channels) per frequency channel (i.e., a mobile handset transmits in only one out of eight available channels during voice communication), which introduces a pulsed signal shape with a pulse repetition rate of 217 Hz. This TDMA frame has a length of 4.6 ms, and 26 TDMA frames make up a multiframe with a duration of 120 ms. For GSM modulations, internal modulation with one time slot active was used.

CDMA Modulation: IS-95 (also known as TIA-EIA-95) was the first CDMA-based digital cellular communication standard. The system’s multiple access is based entirely on code division separation of mobile stations as well as base stations, which implies that the signal structure is significantly different from that of GSM. In the forward downlink, a set of 64 Walsh codes, which are deterministic and orthogonal, are applied to spread/separate the individual channels in the downlink of a cell. After orthogonal spreading, a short 16-bit pseudo noise code is applied to further spread the signal and identify the cell. For IS-95 systems, internal in-phase and quadrature modulation in the signal generator was used with a pseudo random modulation stream, a chip rate of 1.228 Mcps, and a cdmaOne (IS-95) baseband filter. The transmitter transmits continuously, resulting in characteristics that differ substantially from those of the GSM signal.

### 2.3.3 Amplifiers

Each amplifier comprised two RF power modules of ≥175 W each combined with integrated circulators. The outputs were combined using a reactive power combiner followed by an integrated circulator to protect the modules from high reflected power. Reflected power occurs when the antennas in the chamber are not well matched; typically, this occurs when the stirrer blades cross near the antenna. At 900 MHz, the saturated power output of the completed amplifiers was approximately 320 W. The amplifiers had lower output power at 1,900 MHz with the lowest output power being >200 W. Additionally amplifiers were equipped with a limiter to ensure that the maximum output power level did not exceed the safe operation levels and that the maximum reflected power did not exceed the set threshold, as this would increase the dissipation within the amplifier with the potential for permanent damage.

### 2.3.4 Antennas

The antennas were designed to cover both the 900 MHz and 1,900 MHz frequency bands and did not need to be changed when switching from rat exposures at 900 MHz to mouse exposures at 1,900 MHz. Broadband log periodic antennas were designed and custom manufactured (SPEAG, Zürich, Switzerland) to meet the requirements; the maximum dimensions of these antennas were 40 cm long, 20 cm wide, and 2 cm deep. The system had seven antennas, with three antennas in each of the high- and medium-power chambers and one antenna in the low-power chamber. All antennas were placed such that their main beam was aimed at one of the stirrers to maximize the scattering of the field and avoid direct exposure of the animals. All antennas were placed in the rear of the chamber. In the case of the high- and medium-power chambers, antennas were placed in the top left and bottom right and aimed at the stirrer on the rear wall. The other antenna in the top right was aimed at the stirrer on the ceiling. In the low-power chamber, only the antenna in the top right was installed.

### 2.3.5 Exposure Control

The exposure level in any given chamber depended on (i) the number of amplifiers connected to the chamber and (ii) the output power from the amplifiers. The amplifiers that were connected to the different chambers depended on which time slot was being used. These chambers and the studies described in Section 4.2 utilized a 10-minute on/10-minute off alternating exposure paradigm by which animals in each chamber were exposed for 9 hours and 10 minutes per day over an 18-hour and 20-minute exposure period. The first 10-minute time slot had all three amplifiers connected to the high-power chamber (Chamber 1), with each amplifier connected to a different antenna. In the second 10-minute slot, two amplifiers were connected to the medium-power chamber (Chamber 2) and one amplifier was connected to the low-power chamber (Chamber 3). The exposure level in each chamber is a function of the input power to the chamber and the number of animals, weight of animals in the chamber, along with other accessory chamber contents (e.g., number of cages, amount of bedding, and feed). The exposure level was controlled by adjusting the input power to each chamber via a feedback control algorithm to maintain the measured field strength at the target exposure level. The software generated warnings if the measured fields and calculated SAR deviated from the target by more than 2 dB, to alert staff to a potential problem. To ensure the safety of the animals, the exposure was aborted if the SAR exceeded a second set of programmable thresholds, set to 5 dB. Mean SAR levels for the exposures remained within 10% of target levels throughout the studies; summaries of the exposure data are provided in Appendix C. Supporting information, tables, and figures are shown in Appendix A, Section A.7.

### 2.3.6 Chamber Quality Factor and Stirring Performance

Using a vector network analyzer (VNA) connected to two antennas in the reverberation chamber, the loss in energy due to absorption in the individual chamber contents (e.g., racks, bedding, and feed) can be characterized by incrementally placing each component in the chamber and performing measurements over an integral number of stirrer rotations. These measurements were important for the calculation of the power needed to meet the required field strengths, and hence SAR level, in each chamber. The measurement repeatability was assessed and the maximum standard deviation observed at either 900 MHz or 1,900 MHz was 0.05 dB. Supporting information, including tables and figures, and information regarding the measurement of uncertainty is included in Appendix A, Section A.8.

### 2.3.7 Field Uniformity Measurement

Field uniformity was determined via a large number of measurements made over the working volume, both with the chamber empty and fully loaded with racks and phantoms (i.e., animal surrogates). Unlike VNA measurements, field measurements are time consuming. Thus, two elements of the measurement were assessed: the measurement repeatability and the increase in uncertainty as the number of points (i.e., measurement locations) is reduced and the measurement speed is increased. The standard deviation of sets of 900 MHz measurements was <0.2 dB for the total field and 0.3 dB for any given component of the field. The standard deviation of the sets of 1,900 MHz measurements was 0.22 dB for the total field and 0.37 dB for any given orthogonal field component. Supporting information, including tables and figures, and information regarding the measurement of uncertainty and determination of homogeneity is included in Appendix A, Section A.9.

### 2.3.8 Power-Control Simulation

GSM Modulation: To minimize interference between different cells (i.e., base stations), the output power of each handset connected to the GSM network is controlled to the lowest power to achieve reliable communication, which is based on feedback from the base stations. This action results in incremental steps in the power level. The power control has a dynamic range of 30 dB subdivided into 2 dB power-level steps. Power control is typically implemented by means of the slow associated-control channel, which facilitates a power-control update rate no faster than every four multiframes (i.e., 480 ms). Once a target power level is received, the mobile station is able to regulate its power in 2 dB steps every 60 ms (for example, a power regulation over 15 steps [full dynamic range] takes 900 ms). However, GSM base stations typically average the received signal strength from a mobile handset over 1 s, such that the actual power regulation usually takes place after multiples of 480 ms. In summary, the main low-frequency amplitude modulation components of the GSM signal are 217 Hz TDMA frame (provided by the modulation), 8.3 Hz multiframe, 2 Hz discontinuous transmission (DTx), and <1 Hz power control.

CDMA Modulation: In CDMA systems such as IS-95, efficient power control is crucial. Because all mobile stations transmit and interfere in the same frequency channel, each active mobile station decreases the signal to noise ratio of all the other mobiles. Hence, the output power of a mobile handset should be kept to the minimum level that guarantees good voice quality. On the other hand, when moving around, the mobile handset is subject to issues such as slow and fast fading, shadowing, and external interferences. To keep the output power low and compensate for the effects of changing communication channel loss, fast power control is necessary. When an IS-95 mobile station is actively communicating, a closed-loop power control is applied. The base station monitors the signal quality in the reverse link and inserts power control bits in the communication channel, which facilitates power control over a dynamic range of 48 dB in 1 dB steps with an update rate of 800 Hz. The power control is implemented by sending a binary value of 1 to regulate the transmit power down by 1 dB and a value of 0 to regulate the transmit power up by 1 dB. A quasi-static power level is therefore implemented with an alternating 0101 power-control pattern.

Stirrer Modulation for GSM and CDMA Modulations: In each reverberation chamber, field structure is randomly reflected in different directions from the surfaces of the stirrers, which are in turn continuously rotating, the result being that when averaged over time, the field is homogeneous throughout the volume occupied by the cages. By adjusting the rotation rate of the stirrers, the rate of change of the field strength is tuned to mimic the low-frequency amplitude modulation characteristic of each communication standard provided by the different power-control regimes employed. This stirrer-imposed amplitude variation is sometimes referred to as stirrer modulation. During study development, many combinations of stirrer speeds were measured, and those that best represented the extremely low-frequency components for GSM and IS-95 (i.e., CDMA) power control were selected for the exposure experiments. The faster power control of IS-95 CDMA resulted in faster stirrer speeds than those for GSM experiments. Supporting information is included in Appendix A, Section A.10.

## 2.4 Radiofrequency and Environmental Monitoring System

The RF monitoring system comprised two Four Channel Exposure Acquisition System (EASY4) field measurement devices from Schmid & Partner Engineering (SPEAG, Switzerland). Each EASY4 could monitor up to two chambers with two electric field (E-field) probes (EF3DV3, SPEAG, Switzerland) per chamber, with calibration traceable back to national standards. The use of two E-field probes rather than a single sensor greatly reduced the uncertainty. The probes were attached to custom-made DAEasy4 (SPEAG, Switzerland) data acquisition units, which in turn were connected via optical cables to the EASY4. It was important to measure the E-field for SAR control so that changes in losses (e.g., due to the bedding) did not influence the SAR in the animals. The EASY4 measurement server was connected by ethernet to the control computer. Data acquisition units from Keysight (Santa Rosa, CA) were used to collect all environmental data from the sensors and to control the various functions of the amplifiers and warning lights. The control computer included a fully featured control program for exposure and environmental monitoring, developed based on extensive experience with the operation of similar systems. The control program generated log files to document the operation of the system and, based on the most recent body weights of the animals and the SAR levels required, maintained the field strengths in each chamber at the target level.

The chambers were constructed from stainless steel, which has relatively low permeability and hence does not significantly shield or distort the incident magnetic fields. Therefore, all groups, including the room and chamber control animals, were exposed to similar static and extremely low frequency (ELF) fields. The magnetic fields were not explicitly measured within the context of the RF exposures.

Air, temperature, humidity, noise level, light level, and airflow sensors were included for environmental monitoring. Unless specifically requested otherwise, all sensor data were reported in International System of Units (SI units). The noise sensor microphone was housed outside the chamber, connected via a flexible tube into the chamber, to conduct sound out of the high-field environment. An Audix TM1 microphone was employed for the noise measurement, as it has a frequency response extended to approximately 30 kHz. The custom noise measurement was based on two metrics: the average noise level and the peak noise level.

Airflow through the chamber was measured using a F400 series sensor (Degree Controls, Inc, Nashua, NH), and the measured velocity could be related to the number of air changes per hour. Laminar flow elements were added to the outlet manifold (top right of the chamber) to reduce turbulence in the airflow and to increase measurement accuracy. According to the measured airflow, the speed of the fans, two at the chamber air inlet (bottom left of the chamber) and two at the chamber air outlet, could be adjusted using a fan speed controller (with one speed regulator per chamber). The temperature and humidity of the chamber air were measured using EE060 sensors (E+E Elektronik, Engerwitzdorf, Austria) and were assumed to be essentially the same as those of the air in the exposure room, as the power dissipation in each of the chambers increased the temperature in the RF chambers compared to the chamber control (i.e., the chamber without an active radiation antenna) by less than 0.1°C. Supporting information, tables, and figures are shown in Appendix A, Section A.6.

### 2.4.1 Noise Generators

It was observed that at very high-field strengths, the GSM signals created an audible noise at the 217 Hz TDMA slot frequency. The exact origin of this noise was not clear; however, the bright nature of the noise (i.e., the presence of high frequencies) ruled out thermal effects as the origin, as heating and cooling are slow processes. The noise was localized to an induced vibration in the stirrer blades produced by some force or stress on the relatively thin metal of the blades. This noise was present during GSM exposures in the previous NTP studies, as well. Because the modulation-related noise was exposure-dependent, a noise generator to generate “GSM” noise was linked to each sensor pack to mask any differences between the chambers and ensure that all environmental conditions, including noise, across chambers were similar. The GSM noise could be chosen to be employed only during GSM exposures. If used, the noise would be amplified to the required level to ensure approximately equal sound levels in each chamber. No noise was observed with the IS-95 (i.e., CDMA) signal as there is no on/off modulation associated with CDMA because of continuous transmission and a lack of time slots; thus, no noise generator would be used during CDMA exposures.

## 2.5 Detailed Dosimetry

Dosimetry in the fields of health physics and radiation protection is the measurement, calculation, and assessment of the internal exposure to the body. Nonionizing radiation dosimetry within the radiofrequency range is quantified as the SAR. The SAR is expressed in W/kg. It is not possible to measure induced fields or SAR directly in a subject (human or animals), thus the electromagnetic fields that a subject is exposed to are measured and then numerical simulations using different postures of anatomical models are performed representing different species, sexes, and age groups (numerical dosimetry). If the incident field is well characterized, the correlation between incident field conditions and the fields induced in different tissues and organs can be established. However, the correlation needs to be verified experimentally using homogeneous phantoms (experimental dosimetry).

The numerical dosimetry for both rats and mice was reported in Gong et al.^18^ and relates the SAR induced in the bodies (whole-body and tissue-specific) to a given incident field strength within a reverberation chamber environment as a function of the animal’s body weight (Figure 2).

Figure 2

Specific Absorption Rate Sensitivity for Rats at 900 MHz and Mice at 1,900 MHz as a Function of Body Weight Based on Numerical Dosimetry Using Anatomical Models

Figure adapted from Gong et al.^18^ SAR = specific absorption rate.

### 2.5.1 Experimental Verification of the Dosimetry

Experimental dosimetry was performed in the study chambers using the control system designed and fabricated for these studies. During system testing, animal surrogates, or “phantoms” were used. Each phantom consisted of a container of low-dielectric-constant, low-loss material filled with an appropriate volume of tissue-simulating liquid. The aim was to obtain the same whole-body average SAR (SAR_WB_) in the phantom as in a rodent of the same weight. Simulations of full anatomical models of the rat or mouse provided the SAR distribution across all tissues, which was then averaged to provide the overall average SAR. The overall average SAR was then normalized to an incident field strength of 1 V/m to provide the SAR_WB_ sensitivity. Simulations of the phantoms filled with a selection of tissue-simulating liquids were performed, and the tissue-simulating liquid that provided the closest average SAR value was selected. The chosen liquids were not meant to represent the average tissue properties of a rat or mouse but to represent the same absorption, which is related not only to individual tissue properties within the anatomical model but also the inhomogeneous field distribution.

For the male rats, a nominal 0.5 L bottle was filled to the top with approximately 550 mL head-simulating liquid (HSL) (HSL900; SPEAG, Switzerland), with properties ɛ_r_ = 41.5, σ = 0.97 S/m, which provided a good match to the whole-body anatomical rat. From the simulations, the average SAR_WB_ efficiency of the male rat phantom was determined to be 5.556 × 10^−5^ (W/kg)/(V^2^/m^2^).

For the physical mouse phantom, a nominal 50 mL conical centrifuge tube filled to the top with 55 mL of HSL1900 tissue-simulating liquid (SPEAG, Switzerland), with properties ɛ_r_ = 40.0, σ = 1.40 S/m, provided the best match to the SAR_WB_ efficiency of the mouse. The average SAR_WB_ efficiency for the mouse phantom was 1.50 × 10^−4^ (W/kg)/(V^2^/m^2^).

The SAR in the animal phantoms was assessed experimentally using the temperature method. In this method, animal phantoms were exposed to RFR in a chamber while the temperature of the liquid was monitored. When a liquid phantom was exposed to RF, the temperature change was measured during RFR application (i.e., the heating phase) and after RF was switched off (i.e., the cooling phase), and the heat transfer time constant τ was determined. By applying the lumped-heat-capacity method described in Heat Transfer,^19^ the liquid temperature followed the differential equation below, based on cooling to the ambient temperature of the environment and RF heating, encompassing a cooling term due to heat loss to the environment and a heating term due to power absorption:

[formula image]

where C_liquid_ is the heat capacity of the tissue-simulating liquid, T is temperature, t is time, τ is the time constant, and ΔT is the temperature increase in the liquid (i.e., T_liquid_ − T_ambient_). Two processes are possible: (1) when RF is on, the liquid temperature increases until an equilibrium state is reached, whereby the rate of heat absorbed due to the RF exposure and the rate of heat loss due to convection and conduction are equal; (2) when RF is off, the liquid cools through heat convection and conduction toward the lower temperature of the environment. The SAR_WB_ values were determined by solving the differential equation for long exposure times (t >> τ) of the heating curve equation when the system was in an equilibrium temperature state:

[formula image]

where C_liquid_ is the heat capacity of the tissue-simulating liquid, τ is the time constant, and ΔT is the temperature increase in the liquid. The determination of SAR_WB_ required that the temperature of the environment was constant and also required measurements of the absolute temperature of the dummy liquid, measurements of the room temperature, and determination of the time constant (τ). The latter was determined by fitting the theoretical curve to the recorded temperature change in the phantom liquid during the heating process and separately for the cooling process. The time constant of the process can be calculated from either the heating or cooling curve; however, the RF power during the warm-up phase of the power amplifiers can vary by several dB, resulting in increased uncertainty, therefore use of the cooling curve is preferred. The stated uncertainty of the temperature probes used in these measurements was ±0.2ºC.

### 2.5.2 Verification of Rat Dosimetry

The 10 male rat phantoms were placed in cages and positioned in the chamber. Two phantoms were equipped with fixed temperature sensors to evaluate the heating and cooling time constants; in the other phantoms only the temperature increase was measured at the end of the heating phase. The target field strength was set to 400 V/m. The E-field strength, air temperature, and phantom temperature were recorded during the course of the experimental dosimetry. To ensure that the ambient temperature did not change significantly, air was circulated through the chamber and cooler outside air let into the room intermittently. The SAR uniformity was determined by measuring the phantoms’ temperature immediately after the power was shut off in as short a time as possible. The cooling of the phantoms was corrected via reference to the two phantoms with temperature probes that were present throughout the experiment. There was good concordance between the SAR calculated from the field strength present and the SAR measured (Appendix A). The uniformity in the male rat phantoms was assessed in the eight phantoms without fixed temperature sensors; the uniformity (standard deviation) in the SAR was 0.36 dB and was within ±0.6 dB of the mean for all phantoms.

### 2.5.3 Verification of Mouse Dosimetry

Ten mouse phantom positions within the chamber were measured using phantoms with temperature sensors installed. The temperature was monitored to determine when it approached a constant value at each location, and the time constant was determined from the cooling curve. The SAR uniformity was determined by measuring and estimating the final temperatures of all phantoms. The cooling time constant was then used to calculate the SAR with temperature probes present throughout the experiment. There was good concordance between the SAR calculated from the field strength present and the SAR measured (Appendix A). The uniformity (standard deviation) in the SAR was 0.5 dB and was within ±0.9 dB of the mean for all phantoms.

### 2.5.4 Verification of the Effect of the Water System on the Dosimetry

The fields around the water system were measured with respect to the fields measured by the two fixed probes in the chamber. At 900 and 1,900 MHz, the field strength at the lixit was well below the nominal chamber field strength, showing that the rats and mice (respectively) would be safe while drinking (i.e., that exposure would not be higher than the target SAR). The field at the flange was similar to the nominal field but within the variation measured during the homogeneity measurement of the empty chamber, which was up to ±3 dB compared to the average field strength.

Numerical and experimental dosimetry was conducted at 900 MHz for rats and at 1,900 MHz for mice using phantoms to assess the SAR when drinking water and when away from the water system. The relative magnitude of the SAR was determined by observing the rate of temperature change at different locations within the phantom, namely, at the mouth, the head, and the center of the body. A 3D-printed shell based on the anatomical models used for the numerical dosimetry was utilized for the rat, whereas a simplified shape was used for the mouse. It was observed that evaporation from the exposed gel surface was a confounding process that could reduce the temperature rise at the mouth if the surface was not covered by a plastic membrane. The results of the rat water system dosimetry showed that the SAR in the mouth and head areas of the rat phantoms was lower when the phantom was “drinking water” than when the phantom was not close to the water system, confirming that the water system would be safe (i.e., that the exposure when the animal was drinking water was not higher than the target SAR). The results of the mouse dosimetry showed that the SAR in the head was the same when the phantom was “drinking water” compared to when the phantom was not close to the water system. In the mouse phantom, a small increase was observed in the mouth, but the SAR was still lower than in the head. The small increase in SAR observed in the mouse phantom mouth would not be sufficient to cause RF burns or other detrimental effects. Supporting information, tables, and figures are shown in Appendix A, Section A.11.

### 2.5.5 Evaluation of Implantable Temperature Sensors

These studies utilized temperature chips to record body temperature following RFR exposure. The devices were similar to those used in the previous NTP thermal pilot studies.^15^ To build on these methods of measuring temperature, National Institute of Environmental Health Sciences Division of Translational Toxicology scientists identified another temperature recording device that was compatible with RFR exposure, namely nano-T data loggers (Star-Oddi, Gardebaer, Iceland). Larger devices, capable of measuring heart rate, from Star-Oddi (e.g., micro-HRT sensors) were also evaluated and were determined not to be compatible with RFR exposure. More information on that evaluation can be found in Appendix A, Section A.11.6.

In selecting this new method, safety and compatibility were evaluated prior to testing in animals. From a safety perspective, it was confirmed that the presence of the implanted data logger would not lead to an increase in SAR levels and subsequent increased temperature in the surrounding tissue. From a compatibility perspective, the implanted sensor was confirmed to report the correct temperature without interference from the RF fields. Benchtop experiments evaluating these two features are further described in Appendix A, Section A.11.6.

## 2.6 Summary

An RFR field exposure system was designed to enable equivalent exposure conditions to those utilized in the previous NTP 2-year studies^12,13^ and for a smaller number of animals with a smaller facility footprint.

The RF signal generator produced the modulated signals representative of mobile communication signals compliant with the desired standards. For these studies, either GSM or IS-95 (i.e., CDMA) signals were used. The output of the signal generator was split three ways. The level in each of the three paths was individually controlled before being amplified to the desired level and radiated into the desired chamber via antennas, with one antenna for each amplifier. Each chamber had two mode stirrers (rotating metallic structures) that scattered the field, producing a continuously variable field structure within the chamber. When averaged over time, this field was homogeneous and isotropic over the volume in which the rodents were housed.

The electromagnetic field level in each chamber was monitored using two isotropic E-field probes. Given the measured level and deviation from the target, the exposure level could be corrected by increasing or decreasing the power delivered to the chamber. Computer simulations and experimental verification using animal “phantoms” demonstrated that the RFR exposure parameters for both rats and mice were equivalent to those used in the previous NTP studies.