# 1 Overview

## 1.1 Introduction

Cell phones and other commonly used wireless communication devices transmit their signals via radiofrequency radiation (RFR). At high exposure levels, nonionizing RFR can produce a heating effect that can damage tissues and biological systems. However, little is known about the potential health effects of long-term exposure to low levels of RFR, and current exposure guidelines are based on protection from acute injury resulting from thermal effects.

Findings from some epidemiology studies suggest that exposure to RFR from cell phones is associated with brain tumors (gliomas and vestibular schwannomas) in heavy cell phone users,^2-6^ while other studies have not consistently demonstrated a causal link between cell phone RFR and these same tumor types.^7-11^ Interpretation of the results of these epidemiological studies is complicated by methodological issues such as confounding factors and potential recall biases. Additionally, exposures in the general population may not have occurred for a long enough period to account for the long latency period between exposure and the development of neoplasms.

The signal frequency and modulation of the radiofrequency (RF) signal may play a critical role in the potential interaction between RFR and biological tissues. RFR at the 900 and 1,900 MHz frequencies with signal modulating technologies, i.e., Code Division Multiple Access (CDMA) and Global System for Mobile Communications (GSM), used in 2G and 3G networks were previously evaluated in National Toxicology Program (NTP) studies. While 2G and 3G networks using these technologies were largely phased out in the United States in 2022, these networks continue to be used in other parts of the world. Additionally, the 900 and 1,900 MHz frequencies are used in 4G and 5G networks.

To assess the biological plausibility that nonionizing radiation may induce cancer, 2-year chronic toxicity and carcinogenicity studies were previously conducted as part of an NTP research program on cell phone RFR.^12,13^ These previous NTP studies found that exposure to GSM- or CDMA-modulated cell phone RFR at 900 MHz was associated with increases in the incidences of neoplastic lesions in the heart, brain, and adrenal glands of male Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats. Increased incidences of nonneoplastic lesions were also observed in the heart, brain, and prostate gland of male rats, and in the heart, thyroid gland, brain, and adrenal gland of female rats exposed to RFR. The results of these NTP studies supported an earlier assessment by the International Agency for Research on Cancer, which classified exposure to cell phone RFR as possibly carcinogenic to humans (Group 2B).^14^

## 1.2 NTP Toxicology and Carcinogenicity Studies

The previous 2-year chronic toxicity and carcinogenicity studies conducted under the auspices of NTP were led by National Institute of Environmental Health Sciences Division of Translational Toxicology (NIEHS/DTT) scientists who worked with technical experts at the Foundation for Research on Information Technologies in Society (IT’IS Foundation, Zürich, Switzerland) to design and construct a novel RFR exposure system that was used to conduct a series of in vivo studies, including 2-year chronic toxicity and carcinogenicity studies. The RFR exposure system was tested and then independently verified by technical experts at the National Institute of Standards and Technology (NIST).

The approach used in the previous NTP studies included an early phase to investigate the thermal effects of RFR exposure and established maximal acute-exposure levels without significantly altering body temperatures. In these previous 5-day studies, exposure-related increases in body temperatures were observed at exposure levels ≥6 W/kg body weight (W/kg) in male and female Sprague Dawley rats, with exposure levels above 10 W/kg inducing increases in body temperature (≤3°C) and mortality in aged rats.^15^ In B6C3F1/N mice, only sporadic increases in body temperature were observed regardless of sex or age when exposed to GSM or CDMA RFR up to 12 W/kg.^15^

In the previous 28-day studies, exposure of pregnant rats to GSM or CDMA RFR at 9 W/kg from gestation day (GD) 6 through postnatal day (PND) 21 resulted in decreased body weight and increased body temperatures of pregnant rats during gestation and of pregnant rats and their offspring during lactation.^13^ These effects were not observed in male or female mice exposed to RFR up to 15 W/kg for 28 days.^12^

In the previous NTP chronic rat studies, exposure to GSM or CDMA RFR (≥1.5 W/kg) was associated with increased incidences of malignant schwannomas in the heart, malignant gliomas in the brain, and pheochromocytomas in the adrenal medulla.^13^ Comet assay results in male rats after 19 weeks of exposure (CDMA) were positive for DNA damage in the hippocampus.^16^ At the end of the study, survival was significantly increased in all groups of RFR-exposed males compared to control male rats.^13^ In mice, no carcinogenic effects were observed in males or females exposed to RFR.^12^ However, comet assay results in mice after 14 weeks of exposure were positive for DNA damage in the frontal cortex of the brain in males (GSM and CDMA) and in the blood in females (CDMA).^16^ Positive findings in the brain of male mice were specific to the frontal cortex and were not observed in the hippocampus or the cerebellum.^16^

## 1.3 Research Rationale and Goals

The previous NTP experimental studies demonstrated that chronic, low levels of RFR exposure can induce biological changes in a mammalian system (rodents). These study findings were novel and provided biological plausibility for RFR-induced toxicity and carcinogenicity; however, critical knowledge gaps still existed. Evaluating the potential implications of RFR exposure on human health is dependent on understanding the interactions between RFR and biological tissues, the factors that affect those interactions, and the relationship to different magnitudes and patterns of RFR exposure. Appropriately designed experimental studies can provide insights into the relationship between RFR exposure and biological outcomes, such as carcinogenicity in rodents. These insights can then inform a framework for evaluating the potential for human responses given real-world patterns of exposure to lower levels of RFR. When extrapolating from animal studies to human risk assessments for the effects of RFR, many complicating factors make the evaluation of exposure challenging including the various ways people use their cell phones, such as via Bluetooth^®^ headsets or speakerphone, or by putting the device directly next to their ear. Complicating factors also include variation in RFR exposure among individuals due to disparities in signal strength based on geographical location with respect to a cell phone tower.

The logistics and challenges of designing and carrying out high-quality studies on RFR exposure can be difficult. Because of inherent challenges in studying electromagnetic radiation, robust studies on RFR tend to be more complicated than toxicology studies of pharmaceuticals or environmental chemicals. Key considerations for the technical approach are ensuring that experimental animals are consistently exposed to constant levels of RFR, that the chamber design components and any equipment in the chamber do not interfere with delivery of the RFR signal to the animals, that the animals can be monitored in real time while the system is active, that the chamber design and amplification system do not cause undue stress on the animals, and that animal husbandry tasks can be easily performed.

In an effort to better understand some of the findings from the previous NTP studies and extend technical knowledge on the potential biological effects resulting from RFR exposure,^12,13,15,16^ scientists at the NIEHS/DTT worked with technical experts at IT’IS Foundation and the testing facility to design and develop a novel small-scale RFR exposure system based on many of the specifications of the large-scale system developed for the previous NTP studies, but with additional functionality required to conduct follow-on studies. This novel small-scale system was designed to generate multiple RF signals and frequencies used in 2G, 3G, and 4G long-term evolution (LTE) technologies and expanded exposure capabilities not available at the time the previous NTP studies were conducted. Similar to the previous NTP studies, experts from NIST provided independent verification of the system functionality following installation at the testing facility for the current NIEHS/DTT study.

The goal of the research presented in this report was to conduct a series of short-term investigative studies to assess the use of this new small-scale RFR exposure system for toxicological research. These studies aimed to use real-time physiological monitoring of rats and mice to evaluate the impact of RFR exposure on stress, heart rate, and body temperature, and further assess whether RFR exposure causes DNA damage.

To reduce the size of the overall study, a targeted combination of sex-species-modulation was selected to focus primarily on those that induced the most robust effects in the previous NTP studies. In the current studies, male rats were exposed to CDMA or GSM-modulated RFR, and female rats and male mice were exposed to CDMA-modulated RFR.

This report provides in-depth details on the design, construction, function, and testing of the novel small-scale RFR exposure system and the technical challenges associated with its construction and operation. It also provides findings from the investigative studies and compares them to findings from previously published NTP studies on RFR exposure.