# Publication Details

Publisher: National Institute of Environmental Health Sciences

Publishing Location: Research Triangle Park, NC

DOI: https://doi.org/10.22427/NIEHS-RFR

Official citation: Wyde ME, Capstick M, Hall SM, Hooth MJ, Kuster N, Ladbury JM, Roberts GK, Shipkowski KA, Shockley KS, Smith-Roe SL, Stout MD, Walker NJ. 2025. Development and testing of a novel whole-body exposure system for investigative studies of radiofrequency radiation in rodents. Research Triangle Park, NC: National Institute of Environmental Health Sciences.