# Peer Review

The National Institute of Environmental Health Sciences Division of Translational Toxicology (NIEHS/DTT) secured the services of the experts listed below to conduct a peer review by letter of the draft report, Development and Testing of a Novel Whole-body Exposure System for Investigative Studies of Radiofrequency Radiation in Rodents, in November 2024. Reviewer selection and document review followed established NIEHS/DTT practices. The reviewers were charged to:

1. Provide external peer review of the draft report, Development and Testing of a Novel Whole-body Exposure System for Investigative Studies of Radiofrequency Radiation in Rodents.
2. Comment on whether the information in the draft report is clearly stated and objectively presented.

NIEHS/DTT carefully considered the reviewers’ comments in finalizing this report.

## Peer Reviewers

- Frank Barnes, Ph.D.
  Distinguished Professor Emeritus, Department of Electrical, Computer, and Energy Engineering
  University of Colorado
  Boulder, Colorado, USA
- Asimina Kiourti, Ph.D.
  Associate Professor, Department of Electrical and Computer Engineering
  The Ohio State University
  Columbus, Ohio, USA
- J. Mark Cline, D.V.M., Ph.D.
  Professor, Department of Pathology
  Wake Forest School of Medicine
  Winston-Salem, North Carolina, USA
- Matthew LeBaron, Ph.D.
  Toxicologist
  The Dow Chemical Company
  Midland, Michigan, USA
- Susan Felter, Ph.D.
  Vice President, Victor Mills Society
  Procter & Gamble
  Mason, Ohio, USA