# References

1 National Information Standards Organization (NISO). CRediT (Contributor Roles Taxonomy). Baltimore, MD: National Information Standards Organization; 2024. [Accessed: July 26, 2024]. https://credit.niso.org/
2 Choi YJ, Moskowitz JM, Myung SK, Lee YR, Hong YC. Cellular phone use and risk of tumors: Systematic review and meta-analysis. Int J Environ Res Public Health. 2020; 17(21):8079. 33147845
3 Coureau G, Bouvier G, Lebailly P, Fabbro-Peray P, Gruber A, Leffondre K, Guillamo JS, Loiseau H, Mathoulin-Pélissier S, Salamon R, et al. Mobile phone use and brain tumours in the CERENAT case-control study. Occup Environ Med. 2014; 71(7):514–522. 24816517
4 Hardell L, Carlberg M, Söderqvist F, Mild KH. Pooled analysis of case-control studies on acoustic neuroma diagnosed 1997-2003 and 2007-2009 and use of mobile and cordless phones. Int J Oncol. 2013; 43(4):1036–1044. 23877578
5 INTERPHONE Study Group. Brain tumour risk in relation to mobile telephone use: Results of the INTERPHONE international case-control study. Int J Epidemiol. 2010; 39(3):675–694. 20483835
6 INTERPHONE Study Group. Acoustic neuroma risk in relation to mobile telephone use: Results of the INTERPHONE international case-control study. Cancer Epidemiol. 2011; 35(5):453–464. 21862434
7 Benson VS, Pirie K, Schüz J, Reeves GK, Beral V, Green J, Million Women Study Collaborators. Mobile phone use and risk of brain neoplasms and other cancers: Prospective study. Int J Epidemiol. 2013; 42(3):792–802. 23657200
8 Feychting M, Schüz J, Toledano MB, Vermeulen R, Auvinen A, Harbo Poulsen A, Deltour I, Smith RB, Heller J, Kromhout H, et al. Mobile phone use and brain tumour risk – COSMOS, a prospective cohort study. Environ Int. 2024;185:108552. 38458118
9 Pettersson D, Mathiesen T, Prochazka M, Bergenheim T, Florentzson R, Harder H, Nyberg G, Siesjö P, Feychting M. Long-term mobile phone use and acoustic neuroma risk. Epidemiology. 2014; 25(2):233–241. 24434752
10 Repacholi MH, Lerchl A, Röösli M, Sienkiewicz Z, Auvinen A, Breckenkamp J, d’Inzeo G, Elliott P, Frei P, Heinrich S, et al. Systematic review of wireless phone use and brain cancer and other head tumors. Bioelectromagnetics. 2012; 33(3):187–206. 22021071
11 Yoon S, Choi JW, Lee E, An H, Choi HD, Kim N. Mobile phone use and risk of glioma: A case-control study in Korea for 2002-2007. Environ Health Toxicol. 2015;30:e2015015. 26726040
12 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies in B6C3F1/N mice exposed to whole-body radio frequency radiation at a frequency (1,900 MHz) and modulations (GSM and CDMA) used by cell phones. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2018. NTP Technical Report No. 596. 10.22427/NTP-TR-596
13 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies in Sprague Dawley (Hsd:Sprague Dawley SD) rats exposed to whole-body radio frequency radiation at a frequency (900 MHz) and modulations (GSM and CDMA) used by cell phones. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2018. NTP Technical Report No. 595. 10.22427/NTP-TR-595
14 International Agency for Research on Cancer (IARC). Non-ionizing radiation, part 2: Radiofrequency electromagnetic fields. (IARC monographs on the evaluation of carcinogenic risks to humans; vol. 102). Lyon, France: International Agency for Research on Cancer; 2013. https://publications.iarc.who.int/126
15 Wyde ME, Horn TL, Capstick MH, Ladbury JM, Koepke G, Wilson PF, Kissling GE, Stout MD, Kuster N, Melnick RL, et al. Effect of cell phone radiofrequency radiation on body temperature in rodents: Pilot studies of the National Toxicology Program’s reverberation chamber exposure system. Bioelectromagnetics. 2018; 39(3):190–199. 29537695
16 Smith-Roe SL, Wyde ME, Stout MD, Winters JW, Hobbs CA, Shepard KG, Green AS, Kissling GE, Shockley KR, Tice RR, et al. Evaluation of the genotoxicity of cell phone radiofrequency radiation in male and female rats and mice following subchronic exposure. Environ Mol Mutagen. 2020; 61(2):276–290. 31633839
17 Capstick M, Kuehn S, Berdinas-Torres V, Gong Y, Wilson P, Ladbury JM, Koepke G, McCormick DL, Gauger J, Melnick RL, et al. A radio frequency radiation exposure system for rodents based on reverberation chambers. IEEE Trans Electromagn Compat. 2017; 59(4):1041–1052. 29217848
18 Gong Y, Capstick MH, Kuehn S, Wilson PF, Ladbury JM, Koepke G, McCormick DL, Melnick RL, Kuster N. Life-time dosimetric assessment for mice and rats exposed in reverberation chambers of the 2-year NTP cancer bioassay study on cell phone radiation. IEEE Trans Electromagn Compat. 2017; 59(6):1798–1808. 29217849
19 Holman JP. Heat transfer. 7th ed. New York, NY: McGraw-Hill; 1990.
20 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.
21 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 5547548
22 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 5037867
23 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145.
24 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill; 1957.
25 U.S. Food and Drug Administration (FDA). 21 CFR Part 58. https://www.ecfr.gov/current/title-21/chapter-I/subchapter-A/part-58
26 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605-627.
27 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Flamm WG, Lorentzen RJ, editors. Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing; 1985. p. 13-59.
28 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67(2):233–241. 7021938
29 Organisation for Economic Co-operation and Development (OECD). Test no. 489: In vivo mammalian alkaline comet assay. OECD guideline for the testing of chemicals. Paris, France: OECD Publishing; 2014. 10.1787/9789264224179-en
30 Brendler-Schwaab S, Hartmann A, Pfuhler S, Speit G. The in vivo comet assay: Use and status in genotoxicity testing. Mutagenesis. 2005; 20(4):245–254. 15899933
31 Burlinson B, Tice RR, Speit G, Agurell E, Brendler-Schwaab SY, Collins AR, Escobar P, Honma M, Kumaravel TS, Nakajima M, et al. Fourth International Workgroup on Genotoxicity Testing: Results of the in vivo comet assay workgroup. Mutat Res. 2007; 627(1):31–35. 17118697
32 Collins AR. The comet assay for DNA damage and repair: Principles, applications, and limitations. Mol Biotechnol. 2004; 26(3):249–261. 15004294
33 Tice RR, Agurell E, Anderson D, Burlinson B, Hartmann A, Kobayashi H, Miyamae Y, Rojas E, Ryu JC, Sasaki YF. Single cell gel/comet assay: Guidelines for in vitro and in vivo genetic toxicology testing. Environ Mol Mutagen. 2000; 35(3):206–221. 10737956
34 Hartmann A, Agurell E, Beevers C, Brendler-Schwaab S, Burlinson B, Clay P, Collins A, Smith A, Speit G, Thybaud V, et al. Recommendations for conducting the in vivo alkaline comet assay. Mutagenesis. 2003; 18(1):45–51. 12473734
35 Pfuhler S, Wolf HU. Detection of DNA-crosslinking agents with the alkaline comet assay. Environ Mol Mutagen. 1996; 27(3):196–201. 8625955
36 National Toxicology Program (NTP). Chemical Effects in Biological Systems (CEBS) data repository: Development and testing of a novel whole-body exposure system for investigative studies of radiofrequency radiation in rodents. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institute of Environmental Health Sciences, National Toxicology Program; 2025. 10.22427/NIEHS-DATA-NIEHS-RFRA
37 Bosquillon de Jenlis A, Del Vecchio F, Delanaud S, Bach V, Pelletier A. Effects of co-exposure to 900 MHz radiofrequency electromagnetic fields and high-level noise on sleep, weight, and food intake parameters in juvenile rats. Environ Pollut. 2020;256:113461. 31706765
38 Broom KA, Findlay R, Addison DS, Goiceanu C, Sienkiewicz Z. Early-life exposure to pulsed LTE radiofrequency fields causes persistent changes in activity and behavior in C57BL/6 J mice. Bioelectromagnetics. 2019; 40(7):498–511. 31522469
39 Spandole-Dinu S, Catrina AM, Voinea OC, Andone A, Radu S, Haidoiu C, Călborean O, Popescu DM, Suhăianu V, Baltag O, et al. Pilot study of the long-term effects of radiofrequency electromagnetic radiation exposure on the mouse brain. Int J Environ Res Public Health. 2023; 20(4):3025. 36833719
40 Ruediger HW. Genotoxic effects of radiofrequency electromagnetic fields. Pathophysiology. 2009; 16(2-3):89–102. 19285841
41 Verschaeve L, Juutilainen J, Lagroye I, Miyakoshi J, Saunders R, de Seze R, Tenforde T, van Rongen E, Veyret B, Xu Z. In vitro and in vivo genotoxicity of radiofrequency fields. Mutat Res. 2010; 705(3):252–268. 20955816
42 Hill DA. Electromagnetic theory of reverberation chambers. Gaithersburg, MD: U.S. Department of Commerce, Technology Administration, National Institute of Standards and Technology; 1998. NIST Technical Note 1506. https://purl.fdlp.gov/GPO/gpo103869
43 Ladbury J, Koepke G, Camell D. Evaluation of the NASA Langley Research Center mode-stirred chamber facility. Gaithersburg, MD: U.S. Department of Commerce, National Institute of Standards and Technology; 1999. NIST Technical Note 1508. https://nvlpubs.nist.gov/nistpubs/Legacy/TN/nbstechnicalnote1508.pdf
44 ITU Radiocommunication Study Groups. Annex 1: Unwanted emission characteristics for IMT-2000 CDMA direct spread radio interface. In: Generic Unwanted Emission Characteristics Associated with the Terrestrial Radio Interfaces of IMT-2000, Revision 1. Geneva, Switzerland: International Telecommunication Union; 1999. 8-1/TEMP/271(Rev.1)-E. https://www.3gpp.org/ftp/tsg_ran/tsg_ran/TSGR_06/Docs/Pdfs/RP-99828.pdf
45 European Telecommunications Standards Institute (ETSI). GSM Technical Specification: Digital cellular telecommunications system (Phase 2+); radio transmission and reception. Sophia Antipolis, France: European Telecommunications Standards Institute; 1996. GSM 05.05 Version 5.1.0: May 1996. https://www.etsi.org/deliver/etsi_gts/05/0505/05.01.00_60/gsmts_0505v050100p.pdf
46 U.S. Food and Drug Administration (FDA). 21 CFR Part 11. https://www.ecfr.gov/current/title-21/chapter-I/subchapter-A/part-11
47 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.