# Acknowledgments

This work was supported by the Intramural Research Program (ES103374 and ES103380) at the National Institute of Environmental Health Sciences (NIEHS), National Institutes of Health and performed for NIEHS under contracts 75N96025C00003, 75N96023A00001, GS-00F-173CA/75N96022F00055, 75N96020C00001, HHSN273201800006C, GS00Q14OADU417 (Order No. HHSN273201600015U), HHSN273201600020C, HHSN273201500006C, HHSN273201400015C⁠⁠^1^, and HHSN273201300004C.

1 These studies were conducted under the NIEHS contract with Battelle Memorial Institute (HHSN273201400015C). The studies were initiated at the Battelle testing facility in West Jefferson, Ohio. On May 1, 2021, the testing facility was transferred to a new company, AmplifyBio. The study was transferred to AmplifyBio as a subcontract under HHS273201400015C. All of the installation and verification activities were conducted while Battelle was the testing facility. For the mouse study, all of the in-life, postmortem, and analytical portions of the study were conducted while Battelle was the testing facility; reporting was conducted under AmplifyBio as the testing facility. The rat studies were conducted under AmplifyBio as the testing facility.