# Appendix G Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NIEHS-DATA-NIEHS-RFRA.^36^

## G.1 Cage Grommet Modification Experiment – Male Rats

I04 – Body Weight Analysis: Evaluation of Male Rats in Different Housing Conditions Following Cage Grommet Modification

I04 – Body Weight Analysis: Evaluation of Male Rats in Different Housing Conditions

## G.2 CDMA Male Mice

G01 – In Vivo Alkaline Comet Assay Summary Data

I01 – Animal Removal Summary

I02 – Animal Removals

I04 – Body Weight Analysis

I05 – Clinical Observations Summary

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Removal Reasons Data

Video Clinical Observations AM Off

Video Clinical Observations AM On

## G.3 CDMA Rats

G01 – In Vivo Alkaline Comet Assay Summary Data - Female

G01 – In Vivo Alkaline Comet Assay Summary Data - Male

I01 – Animal Removal Summary

I02 – Animal Removals

I04 – Body Weight Analysis

I05 – Clinical Observations Summary

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Removal Reasons Data

Video Clinical Observations AM Off

Video Clinical Observations AM On

## G.4 GSM Male Rats

G01 – In Vivo Alkaline Comet Assay Summary Data

I01 – Animal Removal Summary

I02 – Animal Removals

I04 – Body Weight Analysis

I05 – Clinical Observations Summary

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Removal Reasons Data

Video Clinical Observations AM Off

Video Clinical Observations AM On

Video Clinical Observations PM Off

Video Clinical Observations PM On

## G.5 Current Pesticides Analyzed in Rodent Feed

Current Pesticides Analyzed in Rodent Feed