# Appendix F Sentinel Animal Program

## F.1 Methods

Rodents used in National Institute of Environmental Health Sciences Division of Translational Toxicology studies are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test agents. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test agents.

Blood samples were collected from each sentinel animal via dried blood spot sampling technology. Additionally, fecal samples were collected and tested for endoparasites and Helicobacter species. Pelt swabs were evaluated for the presence of ectoparasites. All samples were processed appropriately with serology, ectoparasites, endoparasites, and Helicobacter testing performed by IDEXX BioAnalytics (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, for determination of the presence of pathogens.

The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed (Table F-1, Table F-2).

## F.2 Results

Rats: All test results were negative.

Mice: All test results were negative.

Table F-1 Methods and Results for Sentinel Animal Testing in Male and Female Rats

Five-day Studies
Collection Time Points | Pre-exposure
Number Examined (Males/Females) | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI) | –
Kilham rat virus (KRV) | –
Lymphocytic choriomeningitis virus (LCMV) | –
Mycoplasma pulmonis | –
Pneumocystis carinii | –
Pneumonia virus of mice (PVM) | –
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | –
Rat minute virus (RMV) | –
Rat parvo virus (RPV) | –
Rat theilovirus (RTV) | –
Reovirus Type 3 (REO3) | –
Sendai | –
Theiler’s murine encephalomyelitis virus (TMEV) | –
Toolan’s H-1 | –
Fecal Polymerase Chain Reaction (PCR)
Helicobacter spp. | –
Helicobacter bilis | –
Helicobacter ganmani | –
Helicobacter hepaticus | –
Helicobacter mastomyrinus | –
Helicobacter rodentium | –
Helicobacter typhlonius | –
Aspiculuris tetraptera | –
Syphacia muris | –
Syphacia obvelata | –
Pelt Swabs
Myocoptes | –
Radfordia/Myobia | –

– = negative.

Table F-2 Methods and Results for Sentinel Animal Testing in Male Mice

Five-day Study
Collection Time Points | Pre-exposure
Number Examined (Males) | 5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Ectromelia virus (ECTV) | –
Epizootic diarrhea of infant mice (EDIM) | –
Lymphocytic choriomeningitis virus (LCMV) | –
Minute virus of mice (MVM) | –
Mouse hepatitis virus (MHV) | –
Mouse norovirus (MNV) | –
Mouse parvovirus (MPV) | –
Mycoplasma pulmonis | –
Pneumonia virus of mice (PVM) | –
Reovirus Type 3 (REO3) | –
Sendai | –
Theiler’s murine encephalomyelitis virus (TMEV) | –
Fecal Polymerase Chain Reaction (PCR)
Helicobacter spp. | –
Helicobacter bilis | –
Helicobacter ganmani | –
Helicobacter hepaticus | –
Helicobacter mastomyrinus | –
Helicobacter rodentium | –
Helicobacter typhlonius | –
Aspiculuris tetraptera | –
Syphacia muris | –
Syphacia obvelata | –
Pelt Swabs
Myocoptes | –
Radfordia/Myobia | –

– = negative.