# Appendix E Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

## E.1 NTP-2000 Feed

Table E-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 22.44
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 4.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table E-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished diet.

Table E-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.45 ± 0.191 | 14.3–14.7 | 4
Crude Fat (% by Weight) | 8.1 ± 0.0816 | 8.0–8.2 | 4
Crude Fiber (% by Weight) | 9.96 ± 0.312 | 9.68–10.4 | 4
Ash (% by Weight) | 5.31 ± 0.252 | 5.07–5.53 | 4
Amino Acids (% of Total Diet)
Arginine | 0.807 ± 0.070 | 0.67–0.97 | 32
Cystine | 0.220 ± 0.021 | 0.15–0.25 | 32
Glycine | 0.704 ± 0.037 | 0.62–0.8 | 32
Histidine | 0.340 ± 0.067 | 0.27–0.68 | 32
Isoleucine | 0.546 ± 0.037 | 0.43–0.66 | 32
Leucine | 1.095 ± 0.060 | 0.96–1.24 | 32
Lysine | 0.698 ± 0.100 | 0.31–0.86 | 32
Methionine | 0.407 ± 0.039 | 0.26–0.49 | 32
Phenylalanine | 0.628 ± 0.035 | 0.54–0.72 | 32
Threonine | 0.513 ± 0.039 | 0.43–0.61 | 32
Tryptophan | 0.168 ± 0.070 | 0.11–0525 | 32
Tyrosine | 0.425 ± 0.063 | 0.28–0.54 | 32
Valine | 0.668 ± 0.042 | 0.55–0.77 | 32
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.920 ± 0.242 | 3.49–4.55 | 32
Linolenic | 0.224 ± 0.134 | 0.004–0.35 | 32
Vitamins
Vitamin A (IU/kg) | 3,353 ± 69 | 2,390–4,040 | 4
α-Tocopherol (ppm) | 74.38 ± 23.62 | 20.3–124.0 | 32
Thiamine (ppm)^a^ | 7.075 ± 0.492 | 6.7–7.8 | 4
Riboflavin (ppm) | 8.02 ± 3.46 | 1.1–17.5 | 32
Niacin (ppm) | 81.46 ± 10.62 | 66.4–107.0 | 32
Pantothenic Acid (ppm) | 28.61 ± 10.7 | 17.4–81.0 | 32
Pyridoxine (ppm)^a^ | 9.60 ± 2.46 | 2.3–14.3 | 32
Folic Acid (ppm) | 1.65 ± 0.47 | 1.15–3.27 | 32
Biotin (ppm) | 0.323 ± 0.112 | 0.0–0.704 | 32
B_12_ (ppb) | 50.57 ± 33.14 | 18.3–174.0 | 32
Choline (as Chloride) (ppm) | 2,537 ± 628 | 1,160–3,790 | 32
Minerals
Calcium (%) | 0.065 ± 0.09 | 0.954–1.15 | 4
Phosphorus (%) | 0.614 ± 0.026 | 0.577–0.635 | 4
Potassium (%) | 0.662 ± 0.035 | 0.569–0.733 | 32
Chloride (%) | 0.395 ± 0.068 | 0.3–0.688 | 32
Sodium (%) | 0.192 ± 0.026 | 0.153–0.283 | 32
Magnesium (%) | 0.216 ± 0.052 | 0.185–0.49 | 32
Iron (ppm) | 181.8 ± 46.27 | 21–311 | 32
Manganese (ppm) | 49.87 ± 8.97 | 21.0–73.1 | 32
Zinc (ppm) | 51.13 ± 9.64 | 18.4–78.5 | 32
Copper (ppm) | 7.70 ± 2.42 | 3.21–16.3 | 32
Iodine (ppm) | 0.50 ± 0.236 | 0–1.0 | 32
Chromium (ppm) | 0.72 ± 0.66 | 0.249–3.97 | 31
Cobalt (ppm) | 0.215 ± 0.146 | 0.086–0.864 | 30

^a^ As hydrochloride.

Table E-4 Contaminant Levels in NTP-2000 Rat and Mouse Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.185 ± 0.020 | 0.169–0.214 | 4
Cadmium (ppm) | 0.062 ± 0.0167 | 0.47–0.085 | 4
Lead (ppm) | 0.085 ± 0.0104 | 0.02–0.08 | 4
Mercury (ppm) | 0.01 ± 0.0034 | 0.005–0.0129 | 4
Selenium (ppm) | 0.0098 ± 0.0034 | 0.107–0.24 | 4
Aflatoxins (ppb)^a^ | <5.0 | – | 4
Nitrate Nitrogen (ppm)^b^ | 9.58 ± 1.42 | 8.67–11.7 | 4
Nitrite Nitrogen (ppm)^b^ | 0.212 ± 0.112 | 0.122–0.355 | 4
BHA (ppm)^c^ | 1.0175 ± 0.035 | 1.0–1.07 | 4
BHT (ppm)^a,c^ | <1.0 | – | 4
Aerobic Plate Count (CFU/g)^d^ | <10.0 | – | 4
Coliform (MPN/g)^d^ | <3 | – | 4
Escherichia coli (MPN/g)^d^ | <3 | – | 4
Salmonella sp. (MPN/g) | Negative | – | 4
Total Nitrosamines (ppb)^e^ | 7.325 ± 3.45 | 3.4–11.7 | 4
N-Nitrosodimethylamine (ppb)^e^ | 2.625 ± 1.86 | 1.5–5.4 | 4
N-Nitrosopyrrolidine (ppb)^e^ | 4.7 ± 2.173 | 1.7–6.3 | 4
Pesticides (ppm) ^f^
Methyl Chlorpyrifos | 0.0315 ± 0.0075 | 0.024–0.039 | 2
Deltamethrin | 0.12 ± 0.0100 | 0.11–0.13 | 2
Malathion | 0.172 ± 0.0814 | 0.068–0.27 | 4
Piperonyl Butoxide | 2.4 | 2.4–2.4 | 1
THPI | 0.015 | 0.015–0.015 | 1

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; THPI = 1,2,3,6-Tetrahydrophthalimide.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ Results of microbiological analyses were less than the limit of detection.

^e^ All values were corrected for percent recovery.

^f^ Only pesticides above the limit of quantitation (LOQ) are listed. All pesticides tested can be found in the Chemical Effects in Biological Systems (CEBS) database.^36^