# Appendix D Genetic Toxicology

## D.1 Comet Assay

### D.1.1 Evaluation Protocol

This report considers biological as well as statistical factors to determine an overall result for the comet assay.

### D.1.2 Collection of Tissue Samples for Genotoxicity Testing

Exposures to Global System for Mobile Communications (GSM)- or Code Division Multiple Access (CDMA)-modulated cell phone radiofrequency radiation continued briefly on the day of necropsy to minimize the time between exposure and collection of tissues for the comet assay. Subsets of animals were removed during successive “off” exposure periods, with representation across exposure groups during each “off” period. Exposures continued for animals that remained in the reverberation chambers until all animals were removed. All animals were necropsied and all tissues of interest were collected within approximately 2 hours and 4 minutes for mice and 2 hours and 50 minutes for rats. Animals were necropsied in the following order: one animal from each exposure group starting with the chamber control group, moving through each of the exposed groups, then rotating back to the chamber control group; animals were necropsied in numerical order within each exposure group. Six different tissues (cerebellum, frontal cortex, hippocampus, liver, heart, and blood) were collected from each animal for the comet assay. The amount of time that elapsed between euthanizing the animal and submerging dissected tissues in cold mincing solution on ice did not exceed 8 minutes for mice and 13 minutes for rats. Specifically, for CDMA mice, all tissues except brain tissues (i.e., cerebellum, frontal cortex, hippocampus) were submerged within 5 minutes; all brain tissues were submerged within 8 minutes. For CDMA male rats, heart tissue was submerged within 13 minutes, and brain tissues were submerged within 6 minutes; all other tissues from CDMA male rats were submerged within 5 minutes. For CDMA female rats, all tissues were submerged within 7 minutes. For GSM male rats, all tissues were submerged within 8 minutes.

### D.1.3 Comet Assay Protocol

Tissue and peripheral blood samples were analyzed by Integrated Laboratory Systems, LLC, an Inotiv company (ILS; Research Triangle Park, NC) for determination of DNA damage. At termination of the 5-day studies of radiofrequency radiation (RFR), a 50 μL sample of blood was transferred to a tube containing 1 mL of freshly prepared cold mincing buffer ([Mg^+2^, Ca^+2^, and phenol-free Hank’s Balanced Salt Solution [Life Technologies, Carlsbad, CA] with 20 mM EDTA [ethylenediaminetetraacetic acid], pH 7.3 to 7.5, and 10% v/v fresh dimethyl sulfoxide [DMSO]), then frozen in liquid nitrogen. The frontal cortex, hippocampus, cerebellum, liver, and heart were rinsed with cold mincing buffer to remove residual blood, then transferred to individual weigh boats containing sufficient fresh, cold mincing buffer to submerge the tissue and held on ice briefly (≤5 minutes) until processed. Several frozen cubes were prepared from each tissue by cutting small pieces of tissue (3 to 4 mm) and dropping them immediately into a weigh boat containing liquid nitrogen. Tissue cubes were given adequate time to freeze completely and were then transferred to labeled microfuge tubes maintained on dry ice. All samples were subsequently transferred to a −80°C freezer for storage until shipment by overnight courier on dry ice to the analytical laboratory. Upon receipt, all samples were immediately placed in a −80°C freezer for storage until further processing.

Microcentrifuge tubes containing frozen tissue chunks were removed from the −80°C freezer and kept on dry ice until preparation of single cell suspensions in mincing buffer. One milliliter of cold mincing solution was aliquoted into a labeled microcentrifuge tube for each cubed, flash-frozen sample of frontal cortex, cerebellum, liver, and heart (right atrium and ventricle). Because of the small size of the tissue, 0.5 mL of cold mincing solution was aliquoted into a labeled microcentrifuge for each sample of hippocampus. Tubes with cold mincing solution were maintained on ice. Working rapidly to avoid tissue thawing, tissue cubes were transferred to tubes containing the cold mincing solution and rapidly minced until finely dispersed. Minced tissues were immediately processed onto slides. Frozen diluted blood was thawed on ice for immediate processing onto slides.

During slide preparation, freshly prepared minced tissues were maintained on ice and frozen blood samples were allowed to thaw on ice. Just before use, each sample was shaken gently to mix the cells and placed back on ice for 15 to 30 seconds to allow clumps to settle. A portion of the supernatant was empirically diluted with 0.5% low melting point agarose (Lonza, Walkersville, MD) dissolved in Dulbecco’s phosphate buffer (Ca^+2^, Mg^+2^, and phenol-free) at 37°C and layered onto each well of a 2-well or 3-well CometSlide™ (Trevigen, Gaithersburg, MD). For each tissue, slides were prepared in batches of up to 10 animals and then immediately transferred to a refrigerator at 1°C–10°C to solidify the agarose.

Slides were immersed in cold lysing solution (2.5 M NaCl, 100 mM Na_2_EDTA, 10 mM tris(hydroxymethyl)aminomethane (Tris), pH 10, containing freshly added 10% DMSO [Fisher Scientific, Pittsburgh, PA], and 1% Triton X-100) overnight in a refrigerator, protected from light. The following day, the slides were rinsed in 0.4 M Trizma base (pH 7.5), randomly placed onto the platform of a horizontal electrophoresis unit, and treated with cold alkali solution (300 mM NaOH, 1 mM Na_2_EDTA, pH > 13) for 20 minutes to allow DNA unwinding, then electrophoresed at 4°C to 9°C for 20 minutes at 25 V (0.7 V/cm), with a current of approximately 300 mA. After electrophoresis, slides were neutralized with 0.4 M Trizma base (pH 7.5) for 5 minutes and then dehydrated by immersion in absolute ethanol (Pharmco-AAPER, Shelbyville, KY) for at least 5 minutes and allowed to air dry. Slides were prepared in a laboratory with a relative humidity of no more than 60% and stored at room temperature in a desiccator with a relative humidity of no more than 60% until stained and scored; stained slides were stored in a desiccator. NaCl, Na_2_EDTA, Triton X-100, and Trizma base were purchased from Sigma-Aldrich (St. Louis, MO); NaOH was purchased from Fisher Scientific (Pittsburgh, PA).

After staining with SYBR^®^ Gold (Molecular Probes, Life Technologies, Grand Island, NY), the slides, which were independently coded to mask exposure, were scored using Comet Assay IV Imaging Software, Version 4.3.1 (Perceptive Instruments, Ltd., Suffolk, UK), validated for Good Laboratory Practice Part 11 compliance.^46^ In the alkaline (pH > 13) comet assay, damaged nuclear DNA fragments undergo unidirectional migration through the agarose gel within an electrical field, forming an image that resembles a comet, and greater fragmentation leads to increased DNA migration. The image analysis software partitions the intensity of the fluorescent signal of the DNA in the entire comet image into the percentage attributable to the comet head and the percentage attributable to the tail. Manual adjustment of the automated detection of head and tail features is sometimes required. To evaluate DNA damage levels, the extent of DNA migration was characterized for 150 scorable comet figures per animal/tissue as the percent tail DNA (intensity of all tail pixels divided by the total intensity of all pixels in the comet, expressed as a percentage).

Comet figures are classified during the scoring process as scorable (evaluated for the percent tail DNA), nonscorable (because of inability to evaluate the percent tail DNA, for example, if comets overlapped), and “hedgehog.” Hedgehogs either have no defined head (i.e., all DNA appears to be in the tail), or the head and tail appear to be separated. Hedgehogs may represent cells that have sustained high levels of DNA damage and may be apoptotic, although certain data suggest they may represent cells with high levels of repairable DNA damage. Hedgehogs were included in the scoring if they could be adequately recognized by the software. The frequency of hedgehogs was determined by tabulating the number observed in a separate group of 150 cells per animal/tissue.

Although there was no concurrent positive control group in these cell phone RFR studies, slides were made with human TK6 cells treated with ethyl methanesulfonate (standard positive control compound for the comet assay) and were included in each electrophoresis run with each slide set as an internal technical positive control.

### D.1.4 Data Analysis for the Comet Assays

For evaluation of the percent tail DNA, the nonparametric statistical tests selected for trend and for pairwise comparisons with the control group do not make any assumptions about the underlying distribution of measurements and do not require equal variances among the groups. The Jonckheere test is used to test for linear trend and the Dunn test^47^ is used for pairwise comparisons of each RFR-exposed group with the chamber control group. To correct for multiple pairwise comparisons, the p value for each comparison with the control group is multiplied by the number of comparisons made. If this product is greater than 1.00, it is replaced with 1.00. The room control group was compared to the chamber control group using a two-sided Wilcoxon rank-sum test, and results are considered statistically significant if the p value is p ≤ 0.05.

A result is considered positive if the trend test is significant and if at least one exposed group is significantly increased over the control group, or if two or more exposed groups are significantly increased over the corresponding control group. A response is equivocal if only the trend test is significant or if only a single exposed group is significantly increased over the control group. To maintain the overall significance level at 0.05 for positive and equivocal calls, the trend and pairwise differences are considered statistically significant if the one‐sided p value is ≤0.025 (0.05/2).

Although the percent hedgehogs is reported, comet assay results (positive, equivocal, negative) are based solely on the percent tail DNA.

### D.1.5 Results

DNA damage from exposure to RFR was assessed in frontal cortex, hippocampus, cerebellum, liver, blood, and heart cell samples from male mice and male and female rats using the comet assay (Table D-1, Table D-2, Table D-3, and Table D-4). For CDMA male mice, there were no significant increases in DNA damage, measured as the percent tail DNA, in cells sampled from the three brain regions, blood, and heart tissue; there was a significant trend test for the percent tail DNA in liver cells that is of uncertain biological significance. For CDMA male and CDMA female rats, no significant increases in the percent tail DNA were observed for any tissue. For GSM male rats, there were no significant increases in DNA damage, measured as the percent tail DNA, in cells sampled from frontal cortex, cerebellum, liver, blood, or heart tissue; there was a significant trend test for the percent tail DNA in hippocampal cells that is of uncertain biological significance.

The percent tail DNA for room control animals and chamber control animals was not significantly different for 20 of the 24 tissues examined in the 5-day studies. For CDMA male mice, the percent tail DNA was lower in the frontal cortex and higher in the heart in the room control group compared to the chamber control group. For GSM male rats and CDMA female rats, the percent tail DNA in heart tissue was lower in the room control group compared to the chamber control group. For these four instances in which significant differences in the percent tail DNA were detected between the two control groups, the differences did not reach twofold (1.5–1.6-fold) except for the frontal cortex cells in CDMA male mice, which showed a twofold difference in the chamber control group over the room control that may be considered biologically relevant. Notably, negative results were observed in the dose-response studies for each of these four tissues (i.e., heart and frontal cortex in CDMA male mice and heart in GSM male rats and CDMA female rats).

Table D-1 DNA Damage in Male Mice Exposed to Whole-body CDMA-modulated Cell Phone Radiofrequency Radiation for Five Days

| Exposure Level (W/kg) | Percent Tail DNA^a^ | P Value^b^ | Percent Hedgehogs^a^
Frontal Cortex | Room Control^c^ | 0.46 ± 0.11 | 0.008 | 1.60 ± 0.39
| 0 | 0.91 ± 0.10 | | 3.20 ± 1.01
| 5 | 1.15 ± 0.24 | 1.000 | 1.60 ± 0.44
| 10 | 0.77 ± 0.12 | 1.000 | 2.00 ± 0.57
| 15 | 1.34 ± 0.30^d^ | 0.954 | 1.33 ± 0.61^d^
| Trend^e^ | p = 0.401
Hippocampus | Room Control | 6.62 ± 1.16 | 0.940 | 2.87 ± 0.66
| 0 | 6.89 ± 1.49 | | 4.47 ± 2.06
| 5 | 9.19 ± 0.94 | 0.175 | 3.87 ± 1.18
| 10 | 4.94 ± 0.89 | 1.000 | 3.40 ± 0.72
| 15 | 7.17 ± 1.42 | 1.000 | 2.60 ± 1.24
| Trend | p = 0.727
Cerebellum | Room Control | 3.13 ± 0.47 | 0.174 | 1.00 ± 0.27
| 0 | 2.50 ± 0.60 | | 0.53 ± 0.17
| 5 | 2.55 ± 0.28 | 0.566 | 1.07 ± 0.30
| 10 | 3.37 ± 0.95 | 0.936 | 0.60 ± 0.12
| 15 | 4.28 ± 2.37^d^ | 1.000 | 0.74 ± 0.28^d^
| Trend | p = 0.550
Liver | Room Control | 4.78 ± 0.78 | 0.326 | 8.87 ± 1.80
| 0 | 6.05 ± 0.93 | | 12.07 ± 3.23
| 5 | 6.94 ± 1.88 | 1.000 | 7.40 ± 1.67
| 10 | 11.80 ± 2.35 | 0.080 | 9.20 ± 2.14
| 15 | 10.58 ± 1.50 | 0.080 | 14.27 ± 3.19
| Trend | p = 0.010
Heart | Room Control | 7.73 ± 0.92 | 0.004 | 2.93 ± 0.81
| 0 | 4.78 ± 0.43 | | 1.27 ± 0.36
| 5 | 4.95 ± 0.29 | 1.000 | 2.00 ± 0.38
| 10 | 4.98 ± 0.45 | 1.000 | 2.73 ± 0.76
| 15 | 5.60 ± 0.22^d^ | 0.123 | 2.07 ± 0.84^d^
| Trend | p = 0.054
Blood | Room Control | 1.02 ± 0.16 | 0.650 | 1.47 ± 0.47
| 0 | 0.91 ± 0.13 | | 1.13 ± 0.47
| 5 | 1.10 ± 0.10 | 0.389 | 1.27 ± 0.32
| 10 | 1.06 ± 0.14 | 0.701 | 1.60 ± 0.46
| 15 | 1.19 ± 0.10 | 0.144 | 1.33 ± 0.36
| Trend | p = 0.077

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

^a^ Data are presented as mean ± standard error; n = 10.

^b^ Pairwise comparisons for exposed groups with 0 W/kg chamber control group performed using one-sided Dunn test (p ≤ 0.025).

^c^ Pairwise comparison for the room control group compared to the 0 W/kg chamber control group performed using the two-sided Wilcoxon rank-sum test (p ≤ 0.05).

^d^ n = 9.

^e^ Exposure-related trends evaluated by one-sided Jonckheere test (p ≤ 0.025). The room control group was excluded from the trend test.

Table D-2 DNA Damage in Male Rats Exposed to Whole-body CDMA-modulated Cell Phone Radiofrequency Radiation for Five Days

| Exposure Level (W/kg) | Percent Tail DNA^a^ | P Value^b^ | Percent Hedgehogs^a^
Frontal Cortex | Room Control^c^ | 13.14 ± 1.15 | 0.450 | 17.07 ± 1.86
| 0 | 11.54 ± 1.01 | | 20.53 ± 1.86
| 3 | 14.39 ± 0.86 | 0.139 | 22.27 ± 1.53
| 6 | 12.34 ± 1.15 | 1.000 | 15.89 ± 1.09
| 9 | 14.28 ± 1.57 | 0.331 | 18.80 ± 2.27
| Trend^d^ | p = 0.265
Hippocampus | Room Control | 11.55 ± 0.86 | 0.450 | 11.27 ± 2.80
| 0 | 13.14 ± 1.04 | | 11.00 ± 1.33
| 3 | 14.41 ± 1.76 | 0.737 | 14.47 ± 3.77
| 6 | 15.43 ± 2.08 | 0.869 | 16.53 ± 3.50
| 9 | 14.07 ± 1.38 | 0.908 | 11.27 ± 1.74
| Trend | p = 0.298
Cerebellum | Room Control | 6.14 ± 0.48 | 0.450 | 0.93 ± 0.35
| 0 | 5.76 ± 0.48 | | 0.73 ± 0.29
| 3 | 5.16 ± 0.31 | 1.000 | 1.73 ± 0.86
| 6 | 5.43 ± 0.52 | 1.000 | 1.20 ± 0.36
| 9 | 5.49 ± 0.32 | 1.000 | 1.27 ± 0.61
| Trend | p = 0.414
Liver | Room Control | 5.07 ± 0.66 | 0.151 | 14.00 ± 4.20
| 0 | 5.96 ± 0.46 | | 14.93 ± 2.30
| 3 | 7.62 ± 0.40 | 0.064 | 20.33 ± 2.46
| 6 | 7.75 ± 0.82 | 0.133 | 19.50 ± 2.20
| 9 | 5.97 ± 0.90 | 1.000 | 10.13 ± 2.48
| Trend | p = 0.481
Heart | Room Control | 8.76 ± 0.65 | 0.326 | 6.88 ± 1.15
| 0 | 7.53 ± 0.79 | | 5.00 ± 0.68
| 3 | 8.55 ± 0.88 | 0.888 | 4.87 ± 1.08
| 6 | 7.80 ± 0.28 | 1.000 | 4.32 ± 0.91
| 9 | 8.49 ± 0.79 | 0.426 | 3.43 ± 0.79
| Trend | p = 0.161
Blood | Room Control | 6.78 ± 1.98 | 0.096 | 9.07 ± 3.55
| 0 | 11.29 ± 2.39 | | 22.13 ± 4.82
| 3 | 6.15 ± 0.71 | 1.000 | 11.33 ± 1.86
| 6 | 5.61 ± 0.60 | 1.000 | 8.80 ± 1.11
| 9 | 4.90 ± 0.51 | 1.000 | 5.67 ± 1.16
| Trend | p = 0.997

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

^a^ Data are presented as mean ± standard error; n = 10.

^b^ Pairwise comparisons for exposed groups with 0 W/kg chamber control group performed using one-sided Dunn test (p ≤ 0.025).

^c^ Statistical analysis for the room control group compared to the 0 W/kg chamber control group performed using the two-sided Wilcoxon rank-sum test (p ≤ 0.05).

^d^ Exposure-related trends evaluated by one-sided Jonckheere test (p ≤ 0.025). The room control group was excluded from the trend test.

Table D-3 DNA Damage in Female Rats Exposed to Whole-body CDMA-modulated Cell Phone Radiofrequency Radiation for Five Days

| Exposure Level (W/kg) | Percent Tail DNA^a^ | P Value^b^ | Percent Hedgehogs^a^
Frontal Cortex | Room Control^c^ | 8.32 ± 0.83 | 0.762 | 15.07 ± 3.97
| 0 | 8.69 ± 1.07 | | 13.80 ± 3.54
| 3 | 9.73 ± 1.08 | 0.523 | 12.60 ± 3.30
| 6 | 11.43 ± 1.61 | 0.189 | 12.47 ± 2.12
| 9 | 10.95 ± 0.95 | 0.169 | 12.80 ± 1.94
| Trend^d^ | p = 0.043
Hippocampus | Room Control | 6.71 ± 0.59 | 0.597 | 3.00 ± 0.52
| 0 | 7.63 ± 0.85 | | 3.07 ± 0.83
| 3 | 8.15 ± 1.07 | 1.000 | 3.00 ± 0.62
| 6 | 9.90 ± 1.58 | 0.538 | 5.93 ± 1.17
| 9 | 10.26 ± 2.57 | 0.908 | 5.20 ± 1.36
| Trend | p = 0.235
Cerebellum | Room Control | 3.36 ± 0.21 | 0.940 | 7.60 ± 1.35
| 0 | 3.69 ± 0.53 | | 6.87 ± 1.15
| 3 | 3.99 ± 0.65 | 1.000 | 7.33 ± 2.42
| 6 | 3.77 ± 0.47 | 1.000 | 7.67 ± 1.27
| 9 | 4.45 ± 0.59 | 0.413 | 7.73 ± 1.51
| Trend | p = 0.167
Liver | Room Control | 9.61 ± 0.62 | 0.226 | 22.20 ± 2.50
| 0 | 10.85 ± 0.78 | | 23.20 ± 2.42
| 3 | 9.45 ± 1.08 | 1.000 | 15.60 ± 1.41
| 6 | 8.93 ± 0.58 | 1.000 | 18.80 ± 3.24
| 9 | 10.11 ± 0.82 | 1.000 | 19.93 ± 2.81
| Trend | p = 0.773
Heart | Room Control | 8.88 ± 0.98 | 0.013 | 6.20 ± 1.57
| 0 | 13.50 ± 1.21 | | 9.88 ± 2.97
| 3 | 11.95 ± 1.38 | 1.000 | 11.60 ± 2.57
| 6 | 13.92 ± 1.88 | 1.000 | 8.67 ± 1.90
| 9 | 10.58 ± 1.44^e^ | 1.000 | 7.04 ± 1.90^e^
| Trend | p = 0.904
Blood | Room Control | 2.13 ± 0.39 | 0.364 | 8.80 ± 1.61
| 0 | 1.64 ± 0.34 | | 6.20 ± 1.27
| 3 | 2.54 ± 0.56 | 0.253 | 8.93 ± 1.71
| 6 | 1.89 ± 0.74 | 1.000 | 7.60 ± 1.89
| 9 | 2.83 ± 0.39 | 0.061 | 28.47 ± 11.63
| Trend | p = 0.092

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

^a^ Data are presented as mean ± standard error; n = 10.

^b^ Pairwise comparisons for exposed groups with 0 W/kg chamber control group performed using one-sided Dunn test (p ≤ 0.025).

^c^ Statistical analysis for the room control group compared to the 0 W/kg chamber control group performed using the two-sided Wilcoxon rank-sum test (p ≤ 0.05).

^d^ Exposure-related trends evaluated by one-sided Jonckheere test (p ≤ 0.025). The room control group was excluded from the trend test.

^e^ n = 9.

Table D-4 DNA Damage in Male Rats Exposed to Whole-body GSM-modulated Cell Phone Radiofrequency Radiation for Five Days

| Exposure Level (W/kg) | Percent Tail DNA^a^ | P Value^b^ | Percent Hedgehogs^a^
Frontal Cortex | Room Control^c^ | 6.96 ± 0.48 | 0.326 | 4.27 ± 0.90
| 0 | 7.85 ± 0.65 | | 1.87 ± 0.60
| 3 | 7.22 ± 0.56 | 1.000 | 2.60 ± 0.71
| 6 | 7.68 ± 0.60 | 1.000 | 1.80 ± 0.28
| 9 | 8.93 ± 0.38 | 0.196 | 3.27 ± 1.13
| Trend^d^ | p = 0.064
Hippocampus | Room Control | 6.82 ± 0.39 | 0.650 | 0.13 ± 0.09
| 0 | 6.75 ± 0.41 | | 3.60 ± 1.42
| 3 | 6.43 ± 0.37 | 1.000 | 1.47 ± 0.50
| 6 | 8.54 ± 0.64 | 0.073 | 3.40 ± 1.10
| 9 | 9.24 ± 1.12 | 0.064 | 2.60 ± 1.24
| Trend | p = 0.002
Cerebellum | Room Control | 3.98 ± 0.48 | 0.450 | 3.00 ± 0.75
| 0 | 3.47 ± 0.38 | | 2.27 ± 0.52
| 3 | 3.26 ± 0.47 | 1.000 | 2.40 ± 0.51
| 6 | 3.28 ± 0.51 | 1.000 | 1.60 ± 0.33
| 9 | 3.80 ± 0.54 | 1.000 | 2.87 ± 0.53
| Trend | p = 0.386
Liver | Room Control | 5.90 ± 0.84 | 0.880 | 3.27 ± 0.52
| 0 | 5.35 ± 0.43 | | 2.33 ± 0.30
| 3 | 6.80 ± 0.86 | 0.990 | 4.07 ± 0.88
| 6 | 3.59 ± 0.56 | 1.000 | 1.53 ± 0.33
| 9 | 3.50 ± 0.40 | 1.000 | 2.80 ± 0.52
| Trend | p = 0.996
Heart | Room Control | 3.19 ± 0.37 | 0.007 | 3.27 ± 0.46
| 0 | 5.04 ± 0.38 | | 4.07 ± 0.48
| 3 | 4.42 ± 0.26 | 1.000 | 2.93 ± 0.74
| 6 | 5.41 ± 0.57 | 0.949 | 4.93 ± 0.76
| 9 | 4.28 ± 0.28 | 1.000 | 2.47 ± 0.47
| Trend | p = 0.808
Blood | Room Control | 5.87 ± 0.75 | 0.326 | 4.87 ± 2.17
| 0 | 7.90 ± 1.43 | | 18.53 ± 6.17
| 3 | 7.92 ± 0.77 | 1.000 | 15.53 ± 3.10
| 6 | 7.36 ± 1.04 | 1.000 | 19.80 ± 2.87
| 9 | 11.08 ± 1.47 | 0.123 | 23.80 ± 5.33
| Trend | p = 0.053

GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation.

^a^ Data are presented as mean ± standard error; n = 10.

^b^ Pairwise comparisons for exposed groups with 0 W/kg chamber control group performed using one-sided Dunn test (p ≤ 0.025).

^c^ Statistical analysis for the room control group compared to the 0 W/kg chamber control group performed using the two-sided Wilcoxon rank-sum test (p ≤ 0.05).

^d^ Exposure-related trends evaluated by one-sided Jonckheere test (p ≤ 0.025). The room control group was excluded from the trend test.