# Appendix C Exposure Monitoring Data

## C.1 Overview

Exposure data are reported for animals exposed to whole-body radiofrequency radiation (RFR) via signal modulations of Code Division Multiple Access (CDMA) or Global System for Mobile Communications (GSM). Target exposure levels, and acceptable ranges, for rats and mice are reported in Table C-1. Exposure data include specific absorption rate (SAR) levels (W/kg body weight, or W/kg) (Table C-2, Table C-4, Table C-6, and Table C-8), and electric field (E-field) measurements (V/m) (Table C-3, Table C-5, Table C-7, and Table C-9). Fields were measured continuously throughout the studies and measurements were automatically recorded approximately every 20 seconds. For every 20-second interval, the SAR was calculated based on the average E-field data. The data presented for each exposure parameter include the mean and standard deviation [expressed in decibels (dB), W/kg or V/m], the total number of measurements recorded during the identified period of exposure (468/day); the lowest (minimum) and highest measurement (maximum) recorded during the given exposure period; the number of measurements that were within the acceptable range; and the ratio of all measurements within range.

The data reported for SAR also include the animal body weights (g) and the selected target SAR (W/kg) for each group. The data reported for E-field strength include the target range of the field required to maintain appropriate SAR exposures. The minimum and maximum exposure values reported represent a single recorded measurement over the 5-day exposure period. The SAR and chamber field in the control chamber and exposure chambers were within the target ranges (defined as ±2 dB) for 100% of recorded measurements over the course of the study; 100% of E-field exposures in the control chamber and exposure chambers were within the target ranges.

The dB represents a mathematical transformation of a number or numerical ratio using base 10 logarithms. Multiplication of ratios is transformed into addition of dBs; raising a number to a power is transformed into multiplication of dBs.

In general, dB(power) = 10 × log(R) and dB(field) = 20 × log(R). The formulas differ by a factor of 2 because power or SAR varies as the square of the fields. For SAR (in W/kg), the dB formula is calculated as:

SAR (dB) = 10 × log(SAR_M_/SAR_T_)

where SAR_M_ is the measured value and SAR_T_ is the target value, and

−2 dB = 10 × log(SAR_L_/SAR_T_), where SAR_L_ (low) = SAR_T_ × 10^−0.2^

+2 dB = 10 × log(SAR_H_/SAR_T_), where SAR_H_ (high) = SAR_T_ × 10^0.2^

Therefore, the ±2 dB range specified by the National Institute of Environmental Health Sciences Division of Translational Toxicology (NIEHS/DTT) translates to the ranges described in Table C-1 for each SAR used in the 5-day studies.

Table C-1 Target Specific Absorption Rate Levels and Acceptable Specific Absorption Rate Range for the Five-day Studies of Radiofrequency Radiation

Target SAR Level (W/kg) | Acceptable SAR Level Range (W/kg)^a^
Rats
3 | 1.89 to 4.75
6 | 3.79 to 9.51
9 | 5.68 to 14.26
Mice
5 | 3.15 to 7.92
10 | 6.31 to 15.85
15 | 9.46 to 23.77

SAR = specific absorption rate.

^a^ The acceptable SAR range was ±2 dB from the target SAR.

## C.2 Results

### C.2.1 Five-day Studies in Male Mice Exposed to CDMA-modulated Cell Phone Radiofrequency Radiation

Table C-2 Summary of CDMA-modulated Cell Phone Radiofrequency Radiation Exposure Data for Male Mice-Specific Absorption Rate

Chamber | Animal Weight (g) | Target (W/kg) | Mean (W/kg) | Stdev (dB) | Min (dB) | Max (dB) | In Range/Total | Ratio
July 22, 2020
1^a^ | 39.5 | 15.000 | 15.013 | 0.25 | −0.71 | 0.57 | 468/468 | 1.000
2 | 41.3 | 10.000 | 10.006 | 0.13 | −0.55 | 0.59 | 458/458 | 1.000
3 | 40.5 | 5.000 | 5.006 | 0.21 | −0.60 | 0.58 | 458/458 | 1.000
4 | 40.7 | 0.000 | 0.000 | – | – | – | 468/468 | 1.000
July 23, 2020
1 | 39.5 | 15.000 | 15.011 | 0.24 | −0.67 | 0.66 | 468/468 | 1.000
2 | 41.3 | 10.000 | 10.011 | 0.14 | −0.41 | 0.63 | 475/475 | 1.000
3 | 40.5 | 5.000 | 5.008 | 0.21 | −0.58 | 0.55 | 475/475 | 1.000
4 | 40.7 | 0.000 | 0.000 | – | – | – | 468/468 | 1.000
July 24, 2020
1 | 39.5 | 15.000 | 15.013 | 0.23 | −0.55 | 0.58 | 468/468 | 1.000
2 | 41.3 | 10.000 | 10.008 | 0.15 | −0.50 | 1.06 | 459/459 | 1.000
3 | 40.5 | 5.000 | 5.001 | 0.19 | −0.57 | 0.47 | 459/459 | 1.000
4 | 40.7 | 0.000 | 0.000 | – | – | – | 468/468 | 1.000
July 25, 2020
1 | 39.5 | 15.000 | 14.998 | 0.24 | −0.62 | 0.56 | 472/472 | 1.000
2 | 41.3 | 10.000 | 10.006 | 0.13 | −0.36 | 0.50 | 470/470 | 1.000
3 | 40.5 | 5.000 | 5.005 | 0.20 | −0.51 | 0.57 | 470/470 | 1.000
4 | 40.7 | 0.000 | 0.000 | – | – | – | 472/472 | 1.000
July 26, 2020
1 | 39.5 | 15.000 | 15.006 | 0.24 | −0.66 | 0.61 | 466/466 | 1.000
2 | 41.3 | 10.000 | 10.005 | 0.13 | −0.59 | 0.50 | 465/465 | 1.000
3 | 40.5 | 5.000 | 5.004 | 0.20 | −0.61 | 0.52 | 465/465 | 1.000
4 | 40.7 | 0.000 | 0.000 | – | – | – | 466/466 | 1.000

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

^a^ Exposures occurred in 10-minute on, 10-minute off cycles, and due to system power constraints, the 0 W/kg and 15 W/kg groups (Chambers 4 and 1, respectively) were exposed during opposite 10-minute intervals than the 5 W/kg and 10 W/kg (Chambers 2 and 3, respectively) groups.

Table C-3 Summary of CDMA-modulated Cell Phone Radiofrequency Radiation Exposure Data for Male Mice-Averaged E-field

Chamber | Target (V/m) | Mean (V/m) | Stdev (dB) | Min (dB) | Max (dB) | In Range/Total | Ratio
July 22, 2020
1^a^ | 304.4 | 304.4 | 0.25 | −0.71 | 0.57 | 468/468 | 1.000
2 | 252.1 | 252.1 | 0.13 | −0.54 | 0.59 | 458/458 | 1.000
3 | 177.2 | 177.2 | 0.21 | −0.61 | 0.58 | 458/458 | 1.000
4 | 0.0 | 0.0 | – | – | – | 468/468 | 1.000
July 23, 2020
1 | 304.4 | 304.3 | 0.24 | −0.67 | 0.66 | 468/468 | 1.000
2 | 252.1 | 252.2 | 0.15 | −0.41 | 0.63 | 475/475 | 1.000
3 | 177.2 | 177.2 | 0.22 | −0.58 | 0.55 | 475/475 | 1.000
4 | 0.0 | 0.0 | – | – | – | 468/468 | 1.000
July 24, 2020
1 | 304.4 | 304.4 | 0.24 | −0.55 | 0.58 | 468/468 | 1.000
2 | 252.1 | 252.2 | 0.14 | −0.50 | 1.06 | 459/459 | 1.000
3 | 177.2 | 177.1 | 0.19 | −0.57 | 0.47 | 459/459 | 1.000
4 | 0.0 | 0.0 | – | – | – | 468/468 | 1.000
July 25, 2020
1 | 304.4 | 304.2 | 0.24 | −0.62 | 0.56 | 472/472 | 1.000
2 | 252.1 | 252.1 | 0.13 | −0.36 | 0.50 | 470/470 | 1.000
3 | 177.2 | 177.2 | 0.20 | −0.51 | 0.57 | 470/470 | 1.000
4 | 0.0 | 0.0 | – | – | – | 472/472 | 1.000
July 26, 2020
1 | 304.4 | 304.3 | 0.24 | −0.66 | 0.61 | 466/466 | 1.000
2 | 252.1 | 252.1 | 0.13 | −0.59 | 0.51 | 465/465 | 1.000
3 | 177.2 | 177.2 | 0.21 | −0.62 | 0.53 | 465/465 | 1.000
4 | 0.0 | 0.0 | – | – | – | 466/466 | 1.000

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

^a^ Exposures occurred in 10-minute on, 10-minute off cycles, and due to system power constraints, the 0 W/kg and 15 W/kg groups (Chambers 4 and 1, respectively) were exposed during opposite 10-minute intervals than the 5 W/kg and 10 W/kg (Chambers 2 and 3, respectively) groups.

### C.2.2 Five-day Studies in Male Rats Exposed to CDMA-modulated Cell Phone Radiofrequency Radiation

Table C-4 Summary of CDMA-modulated Cell Phone Radiofrequency Radiation Exposure Data for Male Rats-Specific Absorption Rate

Chamber | Animal Weight (g) | Target (W/kg) | Mean (W/kg) | Stdev (dB) | Min (dB) | Max (dB) | In Range/Total | Ratio
October 21, 2021
1^a^ | 388.8 | 9.000 | 9.004 | 0.20 | −0.59 | 0.65 | 462/462 | 1.000
2 | 388.1 | 6.000 | 6.002 | 0.18 | −0.67 | 0.62 | 455/455 | 1.000
3 | 384.7 | 3.000 | 3.002 | 0.16 | −0.60 | 0.54 | 455/455 | 1.000
4 | 382.4 | 0.000 | 0.000 | – | – | – | 462/462 | 1.000
October 22, 2021
1 | 388.8 | 9.000 | 9.003 | 0.19 | −0.72 | 0.59 | 477/477 | 1.000
2 | 388.1 | 6.000 | 6.008 | 0.19 | −0.70 | 1.04 | 477/477 | 1.000
3 | 384.7 | 3.000 | 3.002 | 0.16 | −0.64 | 0.91 | 477/477 | 1.000
4 | 382.4 | 0.000 | 0.000 | – | – | – | 477/477 | 1.000
October 23, 2021
1 | 388.8 | 9.000 | 9.026 | 0.22 | −0.72 | 0.86 | 473/473 | 1.000
2 | 388.1 | 6.000 | 6.004 | 0.21 | −1.02 | 0.82 | 473/473 | 1.000
3 | 384.7 | 3.000 | 3.003 | 0.17 | −0.57 | 0.72 | 473/473 | 1.000
4 | 382.4 | 0.000 | 0.000 | – | – | – | 473/473 | 1.000
October 24, 2021
1 | 388.8 | 9.000 | 9.004 | 0.19 | −0.59 | 0.60 | 477/477 | 1.000
2 | 388.1 | 6.000 | 6.003 | 0.18 | −0.62 | 0.82 | 477/477 | 1.000
3 | 384.7 | 3.000 | 3.001 | 0.16 | −0.88 | 0.61 | 477/477 | 1.000
4 | 382.4 | 0.000 | 0.000 | – | – | – | 477/477 | 1.000
October 25, 2021
1 | 388.8 | 9.000 | 9.014 | 0.22 | −0.96 | 0.89 | 461/461 | 1.000
2 | 388.1 | 6.000 | 6.014 | 0.21 | −0.96 | 0.86 | 475/475 | 1.000
3 | 384.7 | 3.000 | 3.003 | 0.17 | −0.72 | 0.59 | 475/475 | 1.000
4 | 382.4 | 0.000 | 0.000 | – | – | – | 461/461 | 1.000

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

^a^ Exposures occurred in 10-minute on, 10-minute off cycles, and due to system power constraints, the 0 W/kg and 9 W/kg groups (Chambers 4 and 1, respectively) were exposed during opposite 10-minute intervals than the 3 W/kg and 6 W/kg (Chambers 2 and 3, respectively) groups.

Table C-5 Summary of CDMA-modulated Cell Phone Radiofrequency Radiation Exposure Data for Male Rats-Averaged E-field

Chamber | Target (V/m) | Mean (V/m) | Stdev (dB) | Min (dB) | Max (dB) | In Range/Total | Ratio
October 21, 2021
1^a^ | 341.6 | 341.6 | 0.21 | −0.59 | 0.65 | 462/462 | 1.000
2 | 278.8 | 278.8 | 0.18 | −0.67 | 0.62 | 455/455 | 1.000
3 | 196.6 | 196.7 | 0.16 | −0.60 | 0.55 | 455/455 | 1.000
4 | 0.0 | 0.0 | – | – | – | 462/462 | 1.000
October 22, 2021
1 | 341.6 | 341.6 | 0.19 | −0.72 | 0.59 | 477/477 | 1.000
2 | 278.8 | 278.9 | 0.19 | −0.70 | 1.04 | 477/477 | 1.000
3 | 196.6 | 196.7 | 0.16 | −0.63 | 0.91 | 477/477 | 1.000
4 | 0.0 | 0.0 | – | – | – | 477/477 | 1.000
October 23, 2021
1 | 341.6 | 342.0 | 0.22 | −0.71 | 0.86 | 473/473 | 1.000
2 | 278.8 | 278.8 | 0.21 | −1.03 | 0.81 | 473/473 | 1.000
3 | 196.6 | 196.7 | 0.17 | −0.57 | 0.72 | 473/473 | 1.000
4 | 0.0 | 0.0 | – | – | – | 473/473 | 1.000
October 24, 2021
1 | 341.6 | 341.6 | 0.19 | −0.59 | 0.60 | 477/477 | 1.000
2 | 278.8 | 278.8 | 0.18 | −0.62 | 0.81 | 477/477 | 1.000
3 | 196.6 | 196.6 | 0.17 | −0.89 | 0.60 | 477/477 | 1.000
4 | 0.0 | 0.0 | – | – | – | 477/477 | 1.000
October 25, 2021
1 | 341.6 | 341.8 | 0.22 | −0.96 | 0.89 | 461/461 | 1.000
2 | 278.8 | 279.0 | 0.21 | −0.96 | 0.86 | 475/475 | 1.000
3 | 196.6 | 196.7 | 0.17 | −0.73 | 0.59 | 475/475 | 1.000
4 | 0.0 | 0.0 | – | – | – | 461/461 | 1.000

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

^a^ Exposures occurred in 10-minute on, 10-minute off cycles, and due to system power constraints, the 0 W/kg and 9 W/kg groups (Chambers 4 and 1, respectively) were exposed during opposite 10-minute intervals than the 3 W/kg and 6 W/kg (Chambers 2 and 3, respectively) groups.

### C.2.3 Five-day Studies in Female Rats Exposed to CDMA-modulated Cell Phone Radiofrequency Radiation

Table C-6 Summary of CDMA-modulated Cell Phone Radiofrequency Radiation Exposure Data for Female Rats-Specific Absorption Rate

Chamber | Animal Weight (g) | Target (W/kg) | Mean (W/kg) | Stdev (dB) | Min (dB) | Max (dB) | In Range/Total | Ratio
November 18, 2021
1^a^ | 277.0 | 9.000 | 9.006 | 0.17 | −0.54 | 0.61 | 465/465 | 1.000
2 | 275.1 | 6.000 | 5.999 | 0.18 | −1.07 | 0.64 | 471/471 | 1.000
3 | 267.0 | 3.000 | 2.999 | 0.16 | −0.57 | 0.58 | 471/471 | 1.000
4 | 266.5 | 0.000 | 0.000 | – | – | – | 465/465 | 1.000
November 19, 2021
1 | 277.0 | 9.000 | 9.006 | 0.18 | −0.73 | 0.57 | 477/477 | 1.000
2 | 275.1 | 6.000 | 5.999 | 0.15 | −0.59 | 0.62 | 477/477 | 1.000
3 | 267.0 | 3.000 | 3.001 | 0.14 | −0.54 | 0.59 | 477/477 | 1.000
4 | 266.5 | 0.000 | 0.000 | – | – | – | 477/477 | 1.000
November 20, 2021, First Period^b^
1 | 277.0 | 9.000 | 8.998 | 0.09 | −0.14 | 0.22 | 18/18 | 1.000
2 | 275.1 | 6.000 | 5.976 | 0.11 | −0.22 | 0.17 | 18/18 | 1.000
3 | 267.0 | 3.000 | 3.012 | 0.12 | −0.27 | 0.25 | 18/18 | 1.000
4 | 266.5 | 0.000 | 0.000 | – | – | – | 18/18 | 1.000
November 20, 2021, Second Period^b^
1 | 277.0 | 9.000 | 9.002 | 0.14 | −0.65 | 0.60 | 441/441 | 1.000
2 | 275.1 | 6.000 | 6.000 | 0.13 | −0.56 | 0.56 | 446/446 | 1.000
3 | 267.0 | 3.000 | 3.002 | 0.11 | −0.32 | 0.61 | 446/446 | 1.000
4 | 266.5 | 0.000 | 0.000 | – | – | – | 441/441 | 1.000
November 21, 2021^c^
1 | 277.0 | 9.000 | 8.995 | 0.13 | −0.29 | 0.34 | 99/99 | 1.000
2 | 275.1 | 6.000 | 6.006 | 0.12 | −0.27 | 0.50 | 99/99 | 1.000
3 | 267.0 | 3.000 | 3.000 | 0.10 | −0.25 | 0.33 | 99/99 | 1.000
4 | 266.5 | 0.000 | 0.000 | – | – | – | 99/99 | 1.000
November 22, 2021
1 | 277.0 | 9.000 | 9.006 | 0.16 | −0.50 | 0.63 | 461/461 | 1.000
2 | 275.1 | 6.000 | 6.002 | 0.16 | −0.68 | 0.59 | 474/474 | 1.000
3 | 267.0 | 3.000 | 3.003 | 0.16 | −0.56 | 0.57 | 474/474 | 1.000
4 | 266.5 | 0.000 | 0.000 | – | – | – | 461/461 | 1.000
November 23, 2021, First Period^b^
1 | 277.0 | 9.000 | 8.933 | 0.13 | −0.26 | 0.28 | 18/18 | 1.000
2 | 275.1 | 6.000 | 5.983 | 0.15 | −0.38 | 0.14 | 18/18 | 1.000
3 | 267.0 | 3.000 | 2.997 | 0.06 | −0.12 | 0.09 | 18/18 | 1.000
4 | 266.5 | 0.000 | 0.000 | – | – | – | 18/18 | 1.000
November 23, 2021, Second Period^b^
1 | 277.0 | 9.000 | 9.004 | 0.16 | −0.68 | 0.55 | 441/441 | 1.000
2 | 275.1 | 6.000 | 6.001 | 0.17 | −0.77 | 0.58 | 446/446 | 1.000
3 | 267.0 | 3.000 | 3.003 | 0.15 | −0.49 | 0.47 | 446/446 | 1.000
4 | 266.5 | 0.000 | 0.000 | – | – | – | 441/441 | 1.000

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

^a^ Exposures occurred in 10-minute on, 10-minute off cycles, and due to system power constraints, the 0 W/kg and 9 W/kg groups (Chambers 4 and 1, respectively) were exposed during opposite 10-minute intervals than the 3 W/kg and 6 W/kg (Chambers 2 and 3, respectively) groups.

^b^ On November 20 and 23, 2021, exposure ceased prematurely and was restarted. The first period exposed animals for approximately 30 minutes, and the second period exposed for 8 hours and 30 minutes.

^c^ On November 21, 2021, exposure ceased prematurely because Chamber 1 (9 W/kg) was not properly closed following afternoon animal husbandry activities and exposure did not resume until the next day, leading to an exposure of only approximately 2 hours for each chamber. Therefore, animals were exposed for an additional day.

Table C-7 Summary of CDMA-modulated Cell Phone Radiofrequency Radiation Exposure Data for Female Rats-Averaged E-field

Chamber | Target (V/m) | Mean (V/m) | Stdev (dB) | Min (dB) | Max (dB) | In Range/Total | Ratio
November 18, 2021
1^a^ | 309.6 | 309.7 | 0.17 | −0.54 | 0.61 | 465/465 | 1.000
2 | 252.3 | 252.2 | 0.18 | −1.07 | 0.65 | 471/471 | 1.000
3 | 176.9 | 176.8 | 0.16 | −0.58 | 0.58 | 471/471 | 1.000
4 | 0.0 | 0.0 | – | – | – | 465/465 | 1.000
November 19, 2021
1 | 309.6 | 309.7 | 0.18 | −0.73 | 0.57 | 477/477 | 1.000
2 | 252.3 | 252.3 | 0.15 | −0.59 | 0.62 | 477/477 | 1.000
3 | 176.9 | 176.9 | 0.14 | −0.54 | 0.59 | 477/477 | 1.000
4 | 0.0 | 0.0 | – | – | – | 477/477 | 1.000
November 20, 2021, First Period^b^
1 | 309.6 | 309.6 | 0.09 | −0.14 | 0.22 | 18/18 | 1.000
2 | 252.3 | 251.8 | 0.11 | −0.22 | 0.17 | 18/18 | 1.000
3 | 176.9 | 177.2 | 0.12 | −0.27 | 0.26 | 18/18 | 1.000
4 | 0.0 | 0.0 | – | – | – | 18/18 | 1.000
November 20, 2021, Second Period^b^
1 | 309.6 | 309.6 | 0.14 | −0.65 | 0.60 | 441/441 | 1.000
2 | 252.3 | 252.3 | 0.13 | −0.55 | 0.56 | 446/446 | 1.000
3 | 176.9 | 176.9 | 0.11 | −0.31 | 0.61 | 446/446 | 1.000
4 | 0.0 | 0.0 | – | – | – | 441/441 | 1.000
November 21, 2021^c^
1 | 309.6 | 309.5 | 0.13 | −0.29 | 0.34 | 99/99 | 1.000
2 | 252.3 | 252.4 | 0.12 | −0.27 | 0.50 | 99/99 | 1.000
3 | 176.9 | 176.9 | 0.10 | −0.25 | 0.34 | 99/99 | 1.000
4 | 0.0 | 0.0 | – | – | – | 99/99 | 1.000
November 22, 2021
1 | 309.6 | 309.7 | 0.16 | −0.50 | 0.63 | 461/461 | 1.000
2 | 252.3 | 252.3 | 0.16 | −0.68 | 0.60 | 474/474 | 1.000
3 | 176.9 | 176.9 | 0.16 | −0.55 | 0.57 | 474/474 | 1.000
4 | 0.0 | 0.0 | – | – | – | 461/461 | 1.000
November 23, 2021, First Period^d^
1 | 309.6 | 308.4 | 0.14 | −0.26 | 0.28 | 18/18 | 1.000
2 | 252.3 | 251.9 | 0.15 | −0.38 | 0.14 | 18/18 | 1.000
3 | 176.9 | 176.8 | 0.06 | −0.11 | 0.08 | 18/18 | 1.000
4 | 0.0 | 0.0 | – | – | – | 18/18 | 1.000
November 23, 2021, Second Period^b^
1 | 309.6 | 309.7 | 0.16 | −0.68 | 0.55 | 441/441 | 1.000
2 | 252.3 | 252.3 | 0.18 | −0.78 | 0.57 | 446/446 | 1.000
3 | 176.9 | 176.9 | 0.15 | −0.49 | 0.47 | 446/446 | 1.000
4 | 0.0 | 0.0 | – | – | – | 441/441 | 1.000

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

^a^ Exposures occurred in 10-minute on, 10-minute off cycles, and due to system power constraints, the 0 W/kg and 9 W/kg exposure groups (Chambers 4 and 1) were exposed during opposite 10-minute intervals than the 3 W/kg and 6 W/kg exposure (Chambers 2 and 3) groups.

^b^ On November 20 and 23, 2021, exposure ceased prematurely and was restarted. The first period exposed animals for approximately 30 minutes, and the second period exposed for 8 hours and 30 minutes.

^c^ On November 21, 2021, exposure ceased prematurely because Chamber 1 (9 W/kg) was not properly closed following afternoon animal husbandry activities and exposure did not resume until the next day, leading to an exposure of only approximately 2 hours for each chamber. Therefore, animals were exposed for an additional day.

### C.2.4 Five-day Studies in Male Rats Exposed to GSM-modulated Cell Phone Radiofrequency Radiation

Table C-8 Summary of GSM-modulated Cell Phone Radiofrequency Radiation Exposure Data for Male Rats-Specific Absorption Rate

Chamber | Animal Weight (g) | Target (W/kg) | Mean (W/kg) | Stdev (dB) | Min (dB) | Max (dB) | In Range/Total | Ratio
September 30, 2021
1^a^ | 373.2 | 9.000 | 9.001 | 0.20 | −0.62 | 0.74 | 468/468 | 1.000
2 | 360.2 | 6.000 | 5.997 | 0.18 | −0.85 | 0.55 | 468/468 | 1.000
3 | 377.4 | 3.000 | 3.001 | 0.17 | −0.77 | 0.59 | 468/468 | 1.000
4 | 377.7 | 0.000 | 0.000 | – | – | – | 468/468 | 1.000
October 1, 2021
1 | 373.2 | 9.000 | 9.002 | 0.21 | −0.87 | 0.81 | 477/477 | 1.000
2 | 360.2 | 6.000 | 6.005 | 0.18 | −0.54 | 0.61 | 477/477 | 1.000
3 | 377.4 | 3.000 | 3.004 | 0.19 | −0.69 | 0.80 | 477/477 | 1.000
4 | 377.7 | 0.000 | 0.000 | – | – | – | 477/477 | 1.000
October 2, 2021, First Period^b^
1 | 373.2 | 9.000 | 8.987 | 0.15 | −0.36 | 0.39 | 67/67 | 1.000
2 | 360.2 | 6.000 | 5.990 | 0.12 | −0.22 | 0.41 | 60/60 | 1.000
3 | 377.4 | 3.000 | 3.005 | 0.15 | −0.44 | 0.45 | 60/60 | 1.000
4 | 377.7 | 0.000 | 0.000 | – | – | – | 67/67 | 1.000
October 2, 2021, Second Period^b^
1 | 373.2 | 9.000 | 9.001 | 0.22 | −0.69 | 0.78 | 378/378 | 1.000
2 | 360.2 | 6.000 | 6.010 | 0.21 | −0.61 | 0.68 | 378/378 | 1.000
3 | 377.4 | 3.000 | 3.002 | 0.18 | −0.57 | 0.91 | 378/378 | 1.000
4 | 377.7 | 0.000 | 0.000 | – | – | – | 378/378 | 1.000
October 3, 2021
1 | 373.2 | 9.000 | 9.011 | 0.22 | −0.71 | 0.75 | 477/477 | 1.000
2 | 360.2 | 6.000 | 6.009 | 0.20 | −0.61 | 0.97 | 477/477 | 1.000
3 | 377.4 | 3.000 | 3.002 | 0.18 | −0.86 | 0.51 | 477/477 | 1.000
4 | 377.7 | 0.000 | 0.000 | – | – | – | 477/477 | 1.000
October 4, 2021
1 | 373.2 | 9.000 | 9.014 | 0.21 | −0.79 | 0.78 | 470/470 | 1.000
2 | 360.2 | 6.000 | 6.012 | 0.21 | −0.73 | 0.82 | 467/467 | 1.000
3 | 377.4 | 3.000 | 3.004 | 0.18 | −0.72 | 0.68 | 467/467 | 1.000
4 | 377.7 | 0.000 | 0.000 | – | – | – | 470/470 | 1.000

GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation.

^a^ Exposures occurred in 10-minute on, 10-minute off cycles, and due to system power constraints, the 0 W/kg and 9 W/kg groups (Chambers 4 and 1, respectively) were exposed during opposite 10-minute intervals than the 3 W/kg and 6 W/kg (Chambers 2 and 3, respectively) groups.

^b^ On October 2, 2021, exposure was disrupted because of a facility power outage, and the system did not expose for approximately 33 minutes. The first period exposed animals for 1 hour and 20 minutes, and the second period exposed for 7 hours and 10 minutes.

Table C-9 Summary of GSM-modulated Cell Phone Radiofrequency Radiation Exposure Data for Male Rats-Averaged E-field

Chamber | Target (V/m) | Mean (V/m) | Stdev (dB) | Min (dB) | Max (dB) | In Range/Total | Ratio
September 30, 2021
1^a^ | 337.6 | 337.5 | 0.20 | −0.61 | 0.73 | 468/468 | 1.000
2 | 272.8 | 272.7 | 0.18 | −0.85 | 0.55 | 468/468 | 1.000
3 | 195.5 | 195.5 | 0.18 | −0.77 | 0.59 | 468/468 | 1.000
4 | 0.0 | 0.0 | – | – | – | 468/468 | 1.000
October 1, 2021
1 | 337.6 | 337.5 | 0.21 | −0.87 | 0.81 | 477/477 | 1.000
2 | 272.8 | 272.9 | 0.18 | −0.54 | 0.61 | 477/477 | 1.000
3 | 195.5 | 195.6 | 0.19 | −0.70 | 0.80 | 477/477 | 1.000
4 | 0.0 | 0.0 | – | – | – | 477/477 | 1.000
October 2, 2021, First Period^b^
1 | 337.6 | 337.3 | 0.15 | −0.36 | 0.39 | 67/67 | 1.000
2 | 272.8 | 272.6 | 0.12 | −0.21 | 0.41 | 60/60 | 1.000
3 | 195.5 | 195.7 | 0.15 | −0.44 | 0.46 | 60/60 | 1.000
4 | 0.0 | 0.0 | – | – | – | 67/67 | 1.000
October 2, 2021, Second Period^b^
1 | 337.6 | 337.5 | 0.23 | −0.70 | 0.77 | 378/378 | 1.000
2 | 272.8 | 273.0 | 0.21 | −0.61 | 0.68 | 378/378 | 1.000
3 | 192.5 | 195.6 | 0.18 | −0.57 | 0.91 | 378/378 | 1.000
4 | 0.0 | 0.0 | – | – | – | 378/378 | 1.000
October 3, 2021
1 | 337.6 | 337.7 | 0.22 | −0.71 | 0.75 | 477/477 | 1.000
2 | 272.8 | 273.0 | 0.20 | −0.62 | 0.97 | 477/477 | 1.000
3 | 195.5 | 195.6 | 0.18 | −0.85 | 0.51 | 477/477 | 1.000
4 | 0.0 | 0.0 | – | – | – | 477/477 | 1.000
October 4, 2021
1 | 337.6 | 337.8 | 0.21 | −0.79 | 0.78 | 470/470 | 1.000
2 | 272.8 | 273.0 | 0.21 | −0.74 | 0.81 | 467/467 | 1.000
3 | 195.5 | 195.6 | 0.18 | −0.73 | 0.69 | 467/467 | 1.000
4 | 0.0 | 0.0 | – | – | – | 470/470 | 1.000

GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation.

^a^ Exposures occurred in 10-minute on, 10-minute off cycles, and due to system power constraints, the 0 W/kg and 9 W/kg groups (Chambers 4 and 1, respectively) were exposed during opposite 10-minute intervals than the 3 W/kg and 6 W/kg (Chambers 2 and 3, respectively) groups.

^b^ On October 2, 2021, exposure was disrupted because of a facility power outage, and the system did not expose for approximately 33 minutes. The first period exposed animals for 1 hour and 20 minutes, and the second period exposed for 7 hours and 10 minutes.