# Appendix B Verification of Electromagnetic Field Exposure Values in Reverberation Chambers and Measurement of Ambient Fields

## B.1 Introduction

This appendix describes the independent verification of the radiofrequency radiation (RFR) exposure system by the National Institute of Standards and Technology (NIST). To verify the parameters of RFR exposures recorded by the data-capture component exposure system, technical experts from NIST conducted an independent verification of the system following installation and initial testing of the exposure system by the Foundation for Research on Information Technologies in Society (IT’IS Foundation, Zürich, Switzerland) and the testing facility. Specifically, NIST evaluated RFR exposure fields, chamber characteristics (field uniformity), and signal quality.

The Spectrum Technology and Research Division of the NIST Communications Technology Laboratory was tasked to provide an independent verification of the radiofrequency (RF) field characteristics that directly affected animal exposure and dosimetry. These characteristics included electric field intensity, field uniformity throughout the chamber, and quality of the modulation. The NIST measurements were compared to the corresponding values reported by the IT’IS-developed automated control system. The power delivered to each chamber—and hence the exposure field level—was determined through a feedback loop using electric field probes located inside the chamber. These IT’IS field probes provided real-time monitoring of exposure levels. For these exposure verification tests, a NIST-calibrated field probe and an antenna system (Figure B-1) were installed in each chamber simultaneously to verify the field intensity reported by the IT’IS probes. These field intensity measurements were performed in each active chamber (total of three: Chambers 1, 2, and 3), and each chamber was tested at 900 MHz with rat cages and rat phantoms (i.e., animal surrogates) and at 1,900 MHz with mouse cages and mouse phantoms. For each configuration, tests were performed for Global System for Mobile Communications (GSM) and Interim Standard 95 (i.e., IS-95, or Code Division Multiple Access [CDMA]), as well as simple continuous wave (CW) signals. The NIST evaluations at the testing facility in West Jefferson, OH, were performed during the weeks of August 5, 2019, and September 16, 2019. The measurement details and data processing techniques are outlined in this appendix, along with the final measurement results of these tests.

The RF signals generated by the exposure system were generally within the estimated uncertainty bounds, indicating that the chamber fields measured by NIST agreed with the measurements provided by the exposure system’s integrated probes. The magnitude of field variation throughout the volume of the chambers was also consistent with values reported for the chambers in the previous National Toxicology Program (NTP) studies. The quality of the modulated signals was found to be acceptable with regard to distortion and harmonic content. Overall, the NIST evaluation confirmed that the exposure system was operating correctly and RFR exposures were within specifications. These activities were conducted prior to the initiation of any animal studies. Additionally, NIST measured ambient levels of RFR at various locations in the facility to assess any potential differences at different locations across the facility. The data demonstrated that there were no marked differences in exposures among the sites evaluated across the facility. This appendix contains full details of the procedures for measurements and calculations.

## B.2 Reverberation Chambers

An electromagnetic reverberation chamber is an electrically large, high quality factor (Q), multimoded complex cavity in which electromagnetic energy can become statistically uniform by changing boundary conditions, in particular by moving large reflective surfaces or paddles. The field parameter that is directly proportional to the specific absorption rate (SAR) is the square of the time-average electric or magnetic field (power density) in the chamber. The average field was determined by sampling the electric field response of calibrated probes and/or antennas over complete rotations of the revolving metal paddles in each chamber. The variability of the average field throughout the volume of the chamber is the metric used to quantify the field (and hence the SAR) uniformity in the chamber.

## B.3 Field Comparisons

The NIST field measurements for each of the three active chambers were compared to the values returned by the IT’IS system. These data included the effects of the independent probe calibrations, slightly different sampling rates, and the variability (or uniformity) of the average field. The field validation measurements were performed with cages and phantoms in the chamber because the isotropy and homogeneity initially measured by IT’IS were similar for the loaded and unloaded chambers, and it was best to evaluate the chambers in a manner consistent with general operation. The photograph in Figure B-1 includes the NIST receiving antenna and the small three-axis probe in the chamber. The antenna received the signal from the chamber, which was processed by a spectrum analyzer to return total channel power for each sample, which could then be used to estimate the electric field.

Figure B-1

One of the Reverberation Test Chambers at the Testing Facility

Each chamber could be configured with either 10 mouse cages or 10 rat cages. This picture shows a chamber configured with nine rat cages, with the tenth cage space occupied by a dual-ridged horn antenna and each cage containing a phantom that simulates the electromagnetic properties of a rat.

The three-axis probe gave three different direct current (DC) voltages that were related to the field incident on each of the three dipole antennas aligned with the orthogonal Cartesian axes of the probe. These DC voltages were then converted to E-field values using calibration data to determine the equivalent field strength for each sample. The probe had a slow response time. To minimize sampling errors due to fields changing as the paddles rotated, the paddles were held at a fixed position during measurement of each sample. (Note: The paddles turned continuously during the animal tests to give the most uniform time-averaged SAR exposure; here the paddles were stopped only to allow the most accurate recording of the field strength within the constraints of the instrumentation.) Probe voltages and received power from the antenna were recorded at 100 different positions of the paddles.

The IT’IS system used similar three-axis probes, with two E-field probes in each chamber. These probes were calibrated by IT’IS to give their estimate of the fields in the chamber.

## B.4 Measurement Uncertainty

By far, the largest contributor to the overall uncertainty of these measurements was the uniformity of the individual chambers. IT’IS reported uniformities (standard deviation of the mean field over multiple locations) in the empty chamber of 1.2 dB (referred to as isotropy in Appendix A) for a Cartesian component of the field at 900 MHz and 0.7 dB (referred to as homogeneity) for the total field. Each value was 0.1 dB higher in the loaded chamber. At 1,900 MHz, IT’IS reported uniformities of 0.7 dB for a Cartesian component of the field and 0.4 dB for the total field. These values were slightly higher (0.8 and 0.6 dB, respectively) for the loaded chamber.

Another source of uncertainty was the use of a limited number (n = 100) of sample positions. Given a Rayleigh distribution, which typically describes the Cartesian fields in a reverberation chamber, 100 samples will result in uncertainties of approximately 0.45 dB. A final large contributor to the uncertainty was the calibration of the probe, which was estimated to be approximately 0.4 dB. These three terms combined to give an estimated standard uncertainty of approximately 1.4 dB for measurements of Cartesian field at 900 MHz, 1.0 dB for the Cartesian field at 1,900 MHz, and approximately 1.0 dB for measurements of the total field. The expanded uncertainty, assuming a coverage factor of 2 (95% confidence), is approximately 3.0 dB for measurements of Cartesian field and 2.0 dB for measurements of the total field (conservatively). These uncertainties represented how accurate the measurements were expected to be, and agreement between the various measurement systems within this range indicated acceptable performance of the field probes.

## B.5 General Processing

Rather than deal with a wide variety of measured values (Cartesian or total field, electric or magnetic field, and received power) and to allow for easier comparison, all measurements were converted to an estimated equivalent total electric field. From a measurement of mean Cartesian electric field <| E_C_ |>, the mean total field <| ET |> can be estimated by multiplying by 15/8^43^:

[formula image]

Finally, from the power measured from the receiving antenna, the mean Cartesian electric field can be estimated as:

[formula image]

By multiplying <| EC |> by 15/8 as shown above, the mean total field can be estimated as:

[formula image]

In this way, similar values will always be compared.

## B.6 Measurement Results

The estimated total electric field based on measurements of mean Cartesian field is presented first. Each individual Cartesian component is used to estimate an equivalent total electric field using the above relationships. As mentioned earlier, each chamber contained two IT’IS E-field probes. Two charts of the results are given below in Figure B-2. In Figure B-2A all the individual readings and the mean field strength are shown for each configuration; in Figure B-2B, all the field measurements are normalized to the average measured value (mean), and only the deviation from that target is presented. As mentioned above, the expanded uncertainties of such measurements are approximately 3 dB, and appropriate error bars are placed around the mean in each chamber. These charts also show the total field estimate based on measurements of received power from a dual-ridged horn antenna, giving an independent confirmation of the measurements. Overall, the measurements were within the expected range. Given the field uniformity data provided by IT’IS, slightly smaller variations for measurements taken at 1,900 MHz than for measurements taken at 900 MHz might be expected. However, this is not obvious in the data shown in Figure B-2B.

Figure B-2

Total Electric Field Estimated from Each Individual Measured Cartesian Field Component Compared to the Mean and Associated Uncertainty

Panel (A) shows the actual field strength in each chamber. Panel (B) is normalized to the mean and shows only the deviation from that value. The abbreviations shown in the legends of each panel equate to which probe generated the data (IT’IS or NIST), the probe number in the case of the IT’IS data (P1 or P2), and the Cartesian axis of the electrical field component (Ex, Ey, or Ez). For example, “IT’IS P1Ex” corresponds to the x-axis electric field component (“Ex”) of IT’IS probe number 1 (“P1”). Different configurations were derived from the three possible chambers (CH1, CH2, CH3), the two possible frequencies (900 or 1,900 MHz), and the three possible modulations (GSM, IS-95 CDMA, CW). CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation; CH1 = Chamber 1; CH2 = Chamber 2; CH3 = Chamber 3; CW = continuous wave; GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation; IS-95 = International Standard 95.

Measurements of the total electric field calculated directly (root-sum-square) from the individual measured Cartesian field components are examined next. Two charts of the results are given below in Figure B-3. Figure B-3A shows the actual field values, and Figure B-3B is normalized to the mean field strength and shows only the deviation from that target. Here the uncertainties are somewhat reduced to 2.0 dB, and again the measurements generally fall within the expected range. It is interesting to note, however, that there is a difference between IT’IS Probe 1 in Chambers 2 and 3 (note: Probe 1 in Chamber 2 is physically different from Probe 1 in Chamber 3) and the other two probes. The same trend is also apparent in Figure B-2, which shows that all three axes of Probe 1 appear to be biased low relative to all the other data. The total field measured on Probe 1 is still almost within 2.0 dB of the mean field; such an offset is within the range of possibility, but the consistency in the plots is unexpected. It might be possible to verify this by swapping Probe 1 with Probe 2 in Chambers 2 and 3 or by swapping probes between chambers. Regardless, a 2.0 dB offset is unexpected but not problematic.

Figure B-3

Total Electric Field Calculated Directly (Root-Sum-Square) from the Individual Measured Cartesian Field Components Compared to the Mean and Associated Uncertainty

Panel (A) shows the actual field strength in each chamber. Panel (B) is normalized to the mean and shows only the deviation from that value. The abbreviations shown in the legends of each panel equate to which probe generated the data (IT’IS or NIST), the probe number in the case of the IT’IS data (P1 or P2), and the total Cartesian electric field (i.e., ET). For example, “IT’IS P1ET” corresponds to the total electric field (“ET”) of IT’IS probe number 1 (“P1”). Different configurations were derived from the three possible chambers (CH1, CH2, CH3), the two possible frequencies (900 or 1,900 MHz), and the three possible modulations (GSM, IS-95 CDMA, CW). CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation; CH1 = Chamber 1; CH2 = Chamber 2; CH3 = Chamber 3; CW = continuous wave; GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation; IS-95 = International Standard 95.

## B.7 Field Uniformity in a Fully Loaded Chamber

IT’IS performed a very detailed evaluation of the uniformity of the test chambers, both of empty chambers and chambers loaded with phantoms, with the field being sampled at many locations throughout the chamber (Appendix A). During the evaluation summarized above, three electric field probes (one NIST probe and two IT’IS probes) were placed at different locations in each chamber, and each probe contained three dipole antennas, giving nine separate readings of the Cartesian component of the field or three separate readings of the total field. An antenna placed in the chamber gave an additional indication of the Cartesian field. The spread in measured results shown in Figure B-2 and Figure B-3 is consistent with the uniformity evaluation given by IT’IS, supporting its determination of the uniformity.

## B.8 Ambient Fields

In addition to the test exposure fields within the chambers, the ambient field in and around the test chambers, as well as other locations throughout the building, were also of interest since the animals would be exposed to these signals whenever they were not inside the test chambers. For these results, a lower-frequency disc-cone antenna was connected to one spectrum analyzer, and a higher-frequency disc-cone antenna was connected to a second spectrum analyzer. The measurement setup is shown in Figure B-4. The lower-frequency antenna was scanned from 10 MHz to 1 GHz, and the higher-frequency antenna was scanned from 1 to 6.5 GHz. Each spectrum analyzer was set to a max-hold condition to capture the peak signals, and frequency sweeps were taken over a 24-hour period at each location. Only the peak power observed in each location over the measurement period is reported. Because all measurements were taken indoors, there is no knowledge of the angles-of-arrival for the observed signals and there is no way to convert received power to field levels. Similarly, there is no method to convert measurements of received power to SAR without detailed knowledge of any target animal. The results are considered representative of typical results in each area, but it is possible that there were different levels (either higher or lower) outside the time window in which these measurements were taken.

Figure B-4

The Ambient Field Measurement Setup

The antenna made of wire rods, on the right, is a low-frequency disc-cone antenna. The smaller antenna, on the left, is a high-frequency disc-cone antenna. Measurements were taken at four separate locations within the testing facility. The locations included the radiofrequency radiation exposure room and three other locations that represented a large geographic distribution throughout the facility.

Figure B-5 shows the peak received power over 24 hours in the low-frequency band at each of four different locations. Overall, the electromagnetic environments in all locations were similar. The highest observed signals were in the cellular frequency bands around 750 MHz and 873 MHz in Location 2. For reference, the lowest expected test field at the time of this evaluation was approximately 194 V/m at 900 MHz, which would give an average received power of approximately +26 dBm or 46 dB higher than observed at the worst-case location.

Similar results for the high-frequency band are shown in Figure B-6. Once again, the highest levels were observed in Location 2, with the highest signal being cellular signals around 2.1 GHz and general communication signals for wireless networks around 2.4 and 5.2 GHz. The lowest expected test field was approximately 132 V/m at 1,900 MHz, which would give an average received power of approximately +16 dBm or, again, 46 dB higher than that observed at the worst-case location.

Figure B-5

Peak Received Power over 24 Hours in Each of Four Separate Locations in the Low-frequency Band

The locations tested included the room housing the reverberation chambers (i.e., radiofrequency radiation laboratory, or “RFR lab”) and three other locations throughout the testing facility. In general, received power at each of the four locations was similar. Here, the highest observed signal (shown in red) was in Location 2. Other signals were mostly negligible and difficult to distinguish from each other.

Figure B-6

Peak Received Power over 24 Hours in Each of Four Separate Locations in the High-frequency Band

The locations tested included the room housing the reverberation chambers (i.e., radiofrequency radiation laboratory, or “RFR lab”) and three other locations throughout the testing facility. In general, received power at each of the four locations was similar. Here, the highest observed signal (shown in red) was in Location 2. Other signals were mostly negligible and difficult to distinguish from each other.

## B.9 Distortion Measurements of the Modulated Signals

Measurements of the spectra of the modulated signals in high-power chambers were carried out to assess the level of both intermodulation distortion and harmonic distortion. The high-power chambers were studied because the amplifiers used to increase the signal levels in these chambers are generally pushed closer to their nonlinear range when compared to their use in the lower-power chambers. Typically, power amplifiers operating in the nonlinear regime are the primary source of distortion in the electronics of the transmit chain.

Standards organizations judge the level of distortion in a modulated signal by comparing the signal level in the main channel (the desired signal) to the signal level in the adjacent channel (distortion). Often, a “spectrum mask” is provided that specifies the acceptable maximum signal level in the adjacent channel relative to the main channel. An example of this mask from the European Telecommunications Standards Institute (ETSI) for the GSM specification is given in Figure B-7 below. In Figure B-7, the measured power 200 kHz from the center frequency should be at least 30 dB below that in the main channel. This number was used to quantify an acceptable level of distortion in the GSM chamber measurements. The IS-95 (i.e., CDMA) specifications are not based on open standards. They are kept by the Telecommunications Industry Association (TIA), a trade organization. However, the spectrum mask for the CDMA2000 and IMT-2000 (International Mobile Telecommunications-2000) specifications is similar to the mask for the GSM specification and is used here to judge the maximum acceptable level of distortion in the chamber measurements. According to Annex 1, “Unwanted Emission Characteristics for IMT-2000 CDMA Direct Spread Radio Interface,”^44^ the spectrum emission mask requirement is approximately 35 dB below the level in the main channel for the adjacent channel.

Typically, harmonic distortion is not considered in specifications documents since bandpass filters are required that only let the main channel signals through the transmitting system. The signal levels in the harmonics were measured only because they gave an indication of the purity of the generated modulated signals. Values below 50 dB or so from those in the main channel should be low enough to affect the signals only minimally. A signal whose level is 50 dB below the main channel is 100,000 times weaker. This signal level would be hard to detect over and above the main channel signal.

Figure B-7

GSM Spectrum Mask from “Radio Transmission and Reception,” GSM 05.05 May 1996, Version 5.1.0

Figure based on specifications from the European Telecommunications Standards Institute.^45^ GSM = Global System for Mobile Communications.

### B.9.1 Modulation Measurement Results

In the following, representative results of both harmonic distortion and intermodulation distortion measurements are shown. The measurements were carried out using a spectrum analyzer and a dual-ridge guide directional antenna. The measurement parameters for the spectrum analyzer are noted in the figure captions. The antenna was placed in the chamber and its output was fed to the spectrum analyzer through a bulkhead. The unloaded chambers were excited with their respective modulated signals at their specified power levels. The spectrum analyzer “peak hold” feature was enabled so the maximum signal levels were acquired over a period of time in order to assess the distortion.

Figure B-8A shows that the maximum signal level in the adjacent channel (approximately 200 kHz from the center frequency of 900 MHz) is more than 35 dB lower than the signal level at the center frequency, which is below the limit of the acceptable range specified in the GSM specification shown in Figure B-7. Figure B-8B shows that the signal level at the second harmonic at 1,800 MHz is around 60 dB below that of the signal at 900 MHz, which is well within the acceptable range.

Figure B-8

900 MHz GSM Spectra Measured in a High-power Chamber, Normalized to the Highest Measured Power

(A) Fundamental frequency band, peak hold on. The spectral mask limits for GSM transmissions are denoted by the red, dotted lines on the plot. (B) Second harmonic, peak hold on. The spectrum analyzer frequency resolution was approximately 2 kHz. GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation.

Figure B-9 shows the GSM spectra in a high-power mouse chamber at 1,900 MHz. Again, the level of intermodulation distortion (signal level in the adjacent channel around the carrier frequency of 1,900 MHz) in Figure B-9A is approximately 35–37 dB below the maximum. These results are very close to the published specification found in the GSM 05.05^45^ and shown in Figure B-7, as depicted by the dotted red lines in Figure B-9A. Any signal levels near this level will have an insignificant contribution to the total power in the signal. The level of harmonic distortion in Figure B-9B is well within acceptable ranges.

Figure B-9

1,900 MHz GSM Spectra Measured in a High-power Chamber

(A) Fundamental, peak hold on. The spectral mask limits for GSM transmissions are denoted by the red, dotted lines on the plot. (B) Second harmonic, peak hold on. The spectrum analyzer frequency resolution was approximately 200 Hz. GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation.

The intermodulation distortion in the highest-power rat and mouse chambers was also measured for the IS-95 (i.e., CDMA) excitation. It is noteworthy that the asymmetry in the lower adjacent channel compared to that of the upper adjacent channel, most noticeably in Figure B-10B, which is not uncommon when wideband modulated signals are amplified. Figure B-10 shows the signal levels in both upper and lower adjacent channels (marked by the vertical dotted lines) are within the specification of approximately 35 dB below the main channel over a 30 kHz frequency bandwidth. The horizontal dotted lines indicate the amplitude threshold limit. Outside the channel, signals need to be below this threshold.

Figure B-10

Interim Standard 95 (i.e., CDMA) Spectrum Measured in a High-power Chamber for (A) 900 MHz and (B) 1,900 MHz

Measurements were conducted in the high-power chamber (Chamber 1). The spectrum analyzer peak hold feature was “on,” and the signal was acquired over several minutes’ time. The spectrum analyzer frequency resolution was approximately 2.4 kHz. CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

Finally, the time-domain waveform associated with the GSM signal in the highest-power rat chamber was measured. Again, the paddles were turning, and the dual-ridge guide antenna was placed in the chamber. The spectrum analyzer was set to “zero span” to acquire the time-domain trace. These measurements were taken to assess possible leakage of signals intended for other chambers through the electronic switches into the chamber of interest.

Figure B-11 shows the maximum level of several repeat measurements overlaid. In each case, the paddle was in a different position, so in some cases the signals were stronger than in other cases. No leak-through was observed, indicating that the maximum possible leak-through signals were at least 70 dB lower than the signals in the desired excitation time slot. High-power radiofrequency switches typically have isolation ratings between 20 and 30 dB between switched channels. The isolation measurements show that the switch exceeded the manufacturer’s specifications.

Figure B-11. Time-domain Waveform Showing Principal Timeslots (High Level) and Timeslots for Other Chambers (Lower Levels)

The spectrum analyzer was set to “zero span” to measure the time-domain waveform.

This appendix indicates that the distortion in the transmission systems used to excite the chambers was minimal. The harmonic distortion was low enough to have a negligible contribution to the total signal power. The intermodulation distortion measured in the adjacent channel was consistent with the spectrum mask for both the GSM and IS-95 (i.e., CDMA) signals. The leak-through from the switches used to excite other chambers was less than 47 dB, well within the specification of such switches and low enough that interference to the main channel should not have been an issue.

## B.10 Conclusions

Overall, each of the chambers behaved as expected. The chamber/IT’IS probe readings were consistent with the calibrated NIST probes, the field uniformity was within expected bounds, and the signal quality was acceptable.

Significant findings include:

- With the exception of a few measured points outside the uncertainty bounds (shown in Figure B-2 and Figure B-3), the electric field measurements agreed within the estimated uncertainty bounds, which indicates that the chamber fields measured by the NIST probe, the NIST reference antenna, and the IT’IS probes agreed within the reported accuracy of each system. For the limited number of measurements outside the uncertainty bounds, they only narrowly exceed the bounds and do not warrant additional concern. The reported exposure field in the chamber was therefore considered reliable.
- The magnitude of field variation throughout the volume of a fully loaded chamber was consistent with earlier values reported on the prototype chamber. However, there may have been up to ±2 dB of variation in the exposure field depending on location in the cage racks. A simple way to mitigate any effect of this exposure variation would be to routinely rotate the cages to various locations in the racks.
- The quality of the modulated signals was found to be acceptable with regard to distortion and harmonic content. The power delivery system appeared to be functioning well within acceptable limits with only minimal leak-through in the switching system.

The overall conclusion is that the system was operating correctly and capable of performing the exposure study.