# Appendix A Chamber Design, Exposure Generation, and Monitoring

## A.1 Introduction

This appendix describes the chambers and control system for the whole-body radiofrequency radiation (RFR) exposure studies. The health and safety features of the system are introduced, along with descriptions of the reverberation chambers, RFR generation and monitoring systems, Global System for Mobile Communications (GSM) and Code Division Multiple Access (CDMA) signal generation, and maintenance of the environmental conditions. This appendix also includes documentation to demonstrate that the chambers function as required with regard to both exposure (including field uniformity) and environmental parameters.

Signal generation and chamber characterization activities were performed by the Foundation for Research on Information Technologies in Society (IT’IS Foundation) at its laboratories in Zürich, Switzerland. Dosimetry was performed in the completed system on phantom (i.e., animal surrogate) rats and mice to determine the influence of the implanted temperature sensors and water system.

## A.2 System Overview

The rodent electromagnetic field exposure system was based on reverberation chambers and included an automatic control system with exposure and environmental condition monitoring and logging. Each reverberation chamber (Figure A-1) was a resonant box in which the resonances and field structure were continuously modified under the influence of metallic stirrers, while shielding the outside environment from the fields inside and vice versa. The system comprised four reverberation chambers: one high specific absorption rate (SAR), one medium SAR, one low SAR, and one with no RFR exposure (i.e., the chamber control). The computer-controlled system consisted of a radiofrequency (RF) source, amplifiers, and data acquisition components. The chambers were equipped with sensors to monitor the exposure and environmental conditions; the computer control system both monitored and recorded the conditions and controlled exposure using these sensors.

An RF signal generator produced the modulated signals representative of mobile communication signals compliant with the desired standards. In these studies, either GSM or Interim Standard 95 (IS-95; i.e., CDMA) signals were used. The output of the signal generator was split three ways and the level in each of the three paths was individually controlled before being amplified to the desired level and radiated into the desired chamber via antennas, with one antenna for each amplifier. Each chamber had two mode stirrers (rotating metallic structures) that scattered the field, producing a continuously variable field structure within the chamber that when averaged over time was homogeneous and isotropic over the volume within which the rodents were housed.

The electromagnetic field level in each chamber was monitored using two isotropic electric field (E-field) probes based on the measured level, and deviation from the target exposure level could be corrected by increasing or decreasing the power delivered to each chamber.

Figure A-1

Internal View of a Reverberation Chamber

## A.3 Chamber Design

Each reverberation chamber was designed to house 10 cages with one animal per cage in Thoren #7 cages with a cage floor area of 474 cm^2^. Based on the homogeneity results of previous analyses that modeled the SAR distribution of RFR across the whole body, rats were exposed at a frequency of 900 MHz, and mice were exposed at 1,900 MHz. Each chamber contained two mode stirrers, one horizontal on the ceiling and one vertical on the rear wall; the stirred volume was 0.29 m^3^ and the chamber volume was 2.31 m^3^, corresponding to 12.5% stirred volume. The doors in two of the chambers were hinged on the right and two were hinged on the left to aid easy access when installed in the exposure room.

The fully welded construction of the chambers ensured no RF leakage from the seams. Internal and external components were shipped separately and were installed onsite so as to:

- Minimize the possibility of damage during transport
- Reduce the external dimensions of the shipping containers to facilitate transport through the hallways at the testing facility from the loading dock to the exposure room

External views of the chamber are depicted in Figure A-2. The features of the chamber design are shown and described in detail in the following sections.

Figure A-2

Front (Left) and Side (Right) Views of the Chamber Designed for the Investigative Studies

Figure A-3

Detailed Features of the Chamber Design (Side View)

NIST = National Institute of Standards and Technology.

### A.3.1 Undercarriage Features

The underside of the chamber (Figure A-4) was designed with integrated U-shaped channels to allow a trolley jack to be slotted in from the front. The channels, which allow the unit to be transported through the facility to the exposure room upon arrival, could be revealed by the removal of a decorative panel that was reinstalled after final positioning in the exposure room. Integrated into the four corners were large adjustable feet that could be used to level the chamber at its final resting position. The feet were accessed for adjustment by removing small side panels. These panels were designed to ensure that any animal that managed to escape could not hide under the chamber.

Figure A-4

View of the Underside of the Chamber Showing the Four Adjustable Feet and the Slots to Allow a Trolley Jack to Be Used for Transport

### A.3.2 Stirrers

The stirrers were designed to have large reflecting surfaces, whereby the angles between the surfaces and angles of rotation with respect to the main axis ensured no radial symmetry (Figure A-5). The mode stirrers were designed like fans, rotating about their axes, but the stirrers reflected electromagnetic fields instead of moving air around with “blades.” By avoiding symmetry, the scattered fields could have higher complexity (Figure A-6) and excite more modes within the chamber volume. The stirrer had six radial elements, each of which was inserted into a hub and held in position with set screws, which allowed individual elements to be removed and replaced.

Figure A-5

Mode Stirrer, Designed with No Symmetry about the Rotational Axis

Figure A-6

Typical Scattered Fields for Different Stirrer Angles (the Lighter the Color, the Higher the Amplitude of the Scattered Field at That Angle)

Each stirrer was driven by a maxon servo motor connected via a 90:1 worm gear. The motor and gear box were mounted by means of rubber isolating mounts that allow some movement and decrease transmitted vibrations. The gear was connected to the stirrer drive shaft via a universal joint that can correct for slight misalignments without causing excessive force or wear. The drive shaft, which was fabricated from a glass-fiber composite, passed through a tube that was sufficiently long and small in radius to provide excellent isolation (Figure A-7). The weight of the stirrers was supported, in the case of the horizontal stirrer, by a conical thrust bearing and, in the case of the vertical stirrer, by two ball bearings. The second bearing was supported by a fiberglass support inside the chamber in front of the stirrer.

Figure A-7

Stirrer Drive Shaft and Bearing

While reviewing videos captured during exposure (see Section 4.2.3.5) it was noted that the stirrer on the back wall of the control chamber (Chamber 4) did not move throughout the four experiments. It is hypothesized that at an unidentified point in time after chamber characterization and before the start of the mouse experiment, the coupling between the motor and the stirrer came loose. As the stirrers were stopped during the animal care and observation periods for safety reasons, the issue was not identified by staff. Furthermore, while a problem with the motor or controller would have been detected by the control software, a mechanical issue like that hypothesized here would not have been detected.

### A.3.3 Airflow and Vents

The temperature and humidity in the chambers were not individually controlled but relied on the control of and sufficient throughput of air from the exposure room. Air was blown into the chamber and extracted from the chamber by means of speed-controlled fans. The fans were chosen to ensure that higher-than-required airflows could be achieved, and the correct number of air changes per hour was obtained by reducing the fan speed as required. Reduction of the fan speed ensured the noise was kept to a minimum. The walls of the chamber had two integrated honeycomb vents (Figure A-8): one located at the rear left and the other at the top front right (Figure A-3). The attenuation of the RF by the honeycomb vent is summarized in Table A-1.

Figure A-9 shows the details of the inlet and outlet manifolds. The inlet manifold had an air filter consisting of a coarse mesh material in front of the Sanyo Denki (Tokyo, Japan) fans, followed by the honeycomb vent, which prevented the RF from propagating out of the chamber.

Figure A-8

Dimensions of the Air Vent (mm)

Table A-1 Attenuation of the Radiofrequency Provided by the Air Vents

Frequency | Field | Shielding dB^a^
0.4 GHz | Plane wave | 130
1 GHz | Plane wave | 120
10 GHz | Plane wave | 120

^a^ Shielding effectiveness for stainless-steel honeycomb with 3/16-inch hexagonal cell size and 1-inch length.

Figure A-9

Structure and Components of Inlet Manifold (Top) and Outlet Manifold (Bottom)

The length of the outlet manifold was larger than that of the inlet to accommodate the environmental sensors. Air passed through the honeycomb air vent at the outlet; the sensor box was attached to the manifold, with sensors projecting into the airflow to measure temperature, humidity, airflow, light, and noise. The airflow sensor could make reliable readings only when in a laminar flow region. If the fans were mounted directly at the outlet, the airflow would be more turbulent; hence a laminar flow element was placed in front of the fans to maintain a relatively straight flow of air between the honeycomb and laminar flow element.

### A.3.4 Mains Filter

Power was required within the chamber for the lighting. Power and any other electrical connections must be either fully shielded or filtered, and the power must pass through a filter with suitable attenuation characteristics. The mains filters (Schaffner, Luterbach, Switzerland) were inserted into the chamber wall with a plastic box for protection on the outside and a stainless-steel box on the inside of the chamber (Figure A-10). Attenuation characteristics for the installed filter (FN7612-10-M3) are available from the manufacturer.

Figure A-10

Mains Filter Installation

### A.3.5 Lighting

The original intention was to install only flat light emitting diode (LED) lighting panels inside the door of the chamber for direct illumination of the cages. However, after review and discussion, the decision was made to install additional incandescent lighting. A review of available fixtures revealed that the industry has largely progressed to the use of low energy lighting, with a far more limited selection of incandescent fixtures. Especially given the available amount of space in the chambers, few options were available. Two light fixtures were required to achieve the required light levels in the animal cages; rough-service 60 W incandescent bulbs, with a color temperature of 2,700 K and light output of 480 Lumens each, should provide sufficient light. These bulbs nominally have long lifetimes of 20,000 hours, whereas the lifetime of a standard incandescent bulb is typically 2,500 hours. As the efficiency of these bulbs is <5%, approximately 115 W of heat would have been expected to be generated per chamber. Ultimately, halogen-based incandescent bulbs were utilized, improving the efficiency and reducing the heat dissipation without degrading the lifetime of the bulbs. The halogen incandescent bulbs used in this study were very similar to those used in the previous NTP studies and reduced energy consumption by one-quarter to one-third compared to standard incandescent light bulbs. For the mouse study, halogen light bulbs (Philips, Model Number 458018) were used, and for the rat studies, halogen light bulbs (GE, Model Number 70335) were used. Both types of halogen light bulbs were 53 W, with an A19 bulb shape and 120 V. Figure A-11 shows the angled bulkhead light fixture.

Figure A-11

Angled Bulkhead Fixture

The incandescent light fixtures were placed in the rear of the chamber, in front of the stirrers to avoid modulation of the light level as the stirrers rotate. This location was the only location able to accommodate the two 10-inch × 6.13-inch fixtures. The two fixtures were placed on opposite sides of the chamber, with one on the rear right side and another on the rear left side, to provide even illumination; Figure A-12 shows the approximate locations of the two fixtures.

LED corner panels, 1.2 m in length, were installed in both front corners of the chamber. Figure A-13 shows the profile and the frosted diffuser used with these elements, which have a rated power of approximately 25 W. The efficiency of the LEDs was approximately 10-fold higher than that of incandescent lights, and the significantly higher light output allowed the LED lighting to be used as inspection lighting. The LEDs were operated on 24 V DC delivered by a small power supply installed inside the internal electrical filter box. A switch on the box allowed toggling between LED and incandescent lighting in each chamber.

Figure A-12

Locations of Two Angled Bulkhead Light Fixtures

The two angled bulkhead light fixtures are depicted as black ovals. Light fixtures were placed at the rear of the chamber in front of the stirrers. Panel (A) shows the chamber from the front view. Panel (B) shows the chamber from the side view.

Figure A-13

(A) Light Emitting Diode Corner Profile and (B) Typical Waterproof Lighting Strip

### A.3.6 Water System

Two individual water systems were installed, one for use at 900 MHz and the other for use at 1,900 MHz. The water system used during any exposure was dependent on the animal cage chosen. Half of the cages had grommets positioned correctly for operation at 900 MHz for use with rats; the remaining cages had grommets that allowed access to the 1,900 MHz water system for mice. See Section A.11 for more details of the performance.

### A.3.7 National Institute of Standards and Technology Probes

A port was provided on the lower right-hand side of each chamber to allow the electromagnetics expert of the National Institute of Standards and Technology (NIST) to insert probes for verification procedures. Figure A-14 shows such a waveguide port (WGF-12) before installation.

Figure A-14

Waveguide Port for Probes and Optical Fibers

### A.3.8 Chamber Door

A twin finger stock approach was used to achieve the required shielding effectiveness for the door. A rectangular cross section was welded onto the front panel around the location of the door opening, with a U-shaped section on the door itself and finger stock on both inner and outer surfaces (Figure A-15).

Figure A-15

Frame Around Chamber Opening and Finger Stock Gasket Installed on the Door

Panel (A) shows the frame around the chamber opening. Panel (B) shows the finger stock gasket installed on the door. Panel (C) shows a cross-sectional view from above of the relative positions when closed, with the frame of the chamber opening shown at the bottom of the image and the door shown at the top.

Figure A-15 also shows the relative positioning of the door and the fixed frame. Figure A-16 shows the door on the chamber in partially open and closed configurations. The hinges were placed 125 mm away from the closest finger stock gasket, so that the finger stock gasket engaged with the mating frame around the door, allowing it to close with a more linear rather than rotational motion. A latch was used to secure the door in the closed configuration. Triangular strengthening members were placed inside the chamber corners to provide rigidity in proximity to the hinges and the latch.

Figure A-16

Door Installed on the Chamber

Panel (A) shows the front view with the door closed. Panel (B) shows the side view with the door open.

### A.3.9 Chamber Strengthening

The final chamber design is shown in Figure A-17; the left image shows the view from the front without the front panel and door, and the cut-away on the right shows the internal features. Rigidity was provided by the side panels and the base through the bending of the panels around the periphery. However, certain features of the chamber required that the panels remained flat to ensure the connected parts were positioned in orthogonal orientations. To this end, additional U-shaped bracing was added to the external surfaces on either side of the vertical and horizontal stirrers as well as the water system to prevent buckling or rippling of the panels caused by the welding process.

Figure A-17

Views of the Complete Chamber Including the Internal Features

Panel (A) shows the front view of the complete chamber with the front removed. Panel (B) shows the internal features of the chamber with the front wall and one side wall removed.

At connection points on the side of the chambers (i.e., to the field probes or antennas), stainless-steel cable trunking was used to protect cables and connections from damage.

### A.3.10 Caging and Cage Racks

Both rats and mice were housed in the chambers in #7 single rat-size cages from Thoren with dimensions of 308 × 222 × 222 mm (L × W × H) and a cage floor area of 474 cm^2^. The lixit openings were at 82.5 mm and 57.5 mm above the bottoms of the cages for rats and mice, respectively. The cage grommets were ceramic.

The cage rack was mounted internally to the chamber walls, and each cage could be removed for cleaning. The cages with lids slid into the cage racks to a depth set by adjustable stops, ensuring that the cage grommet and lixit were aligned. Below the lixits and above the next cage, a U-shaped channel was added to catch water from any leaking lixit and ensure that the cage below did not become flooded.

## A.4 Safety Features

The system included many safety features. To alert staff to the state of the system and avoid unwanted shutdowns or breaks in exposure, each chamber was equipped with a set of warning lights, shown in Figure A-18. The state of the system was indicated by the colors red for “exposure in progress,” blue for “exposure imminent” or “exposure paused by operator,” and green for “the system is idle and the doors can be safely opened” (e.g., for animal care tasks); a flashing blue light indicated that the door needed to be closed.

Figure A-18

Warning Lights and Interlock Switch

All amplifiers were linked to interlock switches on all chambers (Figure A-19) so that if a situation arose whereby the warning lights were not or could not be heeded, the switches would place the system in a safe state by turning off the power to the RF amplifiers (e.g., RF generation was stopped when a door was open or was not properly closed after animal care functions). The software would then subsequently turn off all other elements of the RF generation signal chain. The interlock circuitry relied on safety switches from Pilz mounted on each chamber door and Pilz safety relays for control of the power to the amplifiers. Figure A-19 shows the wiring diagram used as well as the available indicators. This circuit was hardwired and therefore did not require any software element for the system to be placed in a safe state. Safety was ensured by the removal of main power to the amplifiers in the event that a door was opened. In addition, emergency stop buttons installed in the exposure room and close to the control and amplifier racks allowed the RF power to be immediately removed from the system. The monitoring software tracked any of the events described above and recorded them in the log file.

Figure A-19

Safety Interlock System with Pilz Safety Components

A “watchdog” ensured the system was placed in a safe state for the welfare of the animals if the control computer were to lose power or suffer a software crash. The watchdog was a hardware timer that needed to be reset every 20 seconds by the software control program; if this did not happen, the RF power amplifiers were switched off, ensuring the exposure was terminated.

The airflow through the chambers was monitored to ensure sufficient ventilation for the animals, and warnings/alarms were sounded if the flow were to be reduced below the defined minimum.

Other measured environmental parameters were linked to warning and exposure thresholds (e.g., temperature, humidity, and exposure field strength), designed to abort the experiment if the thresholds were exceeded. In particular, if the exposure field exceeded a given threshold above the target exposure level, the exposure would be aborted. The appropriate thresholds were defined at the time of installation.

## A.5 Illumination

The illumination was assessed using a Voltcraft BL10L light meter. The light levels were lower for the incandescent halogen bulbs than for the LED lighting; however, both were in line with the required light level needed for animal housing.

## A.6 Monitoring System

The monitoring system (Figure A-20) comprised two Four Channel Exposure Acquisition System (EASY4) field measurement devices from Schmid & Partner Engineering (SPEAG), Switzerland. Each EASY4 could monitor up to two chambers with two EF3DV3 electric field (E-field) probes (SPEAG, Switzerland) per chamber, with calibration traceable back to national standards. The use of two E-field probes rather than a single sensor greatly reduced the uncertainty. The probes were attached to custom-made DAEasy4 (SPEAG) data acquisition units, which were in turn connected via optical cables to the EASY4. It was important to measure the E-field for SAR control so that changes in losses (e.g., caused by the bedding becoming wet), did not influence the SAR in the animals. The EASY4 measurement server was connected by ethernet to the control computer. Data acquisition units from Keysight (Santa Rosa, CA) were used to collect all environmental data from the sensors and to control the various functions of the amplifiers and warning lights. The equipment rack is shown in Figure A-21.

The chambers were constructed from stainless steel, which has relatively low permeability and hence does not significantly shield or distort the incident magnetic fields. Therefore, all groups, including the room and chamber control animals, were exposed to similar static and extremely low frequency (ELF) fields. The magnetic fields were not explicitly measured within the context of the RF exposures.

The control computer included a fully featured control program for exposure and environmental monitoring, developed on the basis of IT’IS’ extensive experience with the operation of similar systems. The control program generated log files to document the operation of the system and maintained the field strengths in each chamber at the target level according to the most recent weights of the animals and the SAR levels required. The control computer was capable of generating email messages to notify the staff of the status of the system and produced alarms when any given parameter drifted outside predefined limits, stopping exposure when other limits were exceeded.

Software was provided to process the log files to provide daily and monthly reports on the exposures and environmental parameters. In addition, tools to export particular data from the log files to text files (e.g., .csv format), were provided.

Figure A-20

Example of the Control System (Only Two Chambers Shown)

Figure A-21

Equipment Rack Configuration, Dimensions 1,567 × 553 × 600 mm (H × W × D)

### A.6.1 Sensors

In the outlet manifold for circulated air, temperature, humidity, noise level, light level, and airflow sensors were included for environmental monitoring. Unless specifically requested otherwise, all sensor data were reported in the International System of Units (SI units).

The noise sensor microphone was housed outside the chamber, connected via a flexible tube to the chamber, to conduct sound out of the high-field environment. Different possible weightings could be applied to the noise measurement; dBA (A-weighted), a common measure, is the weighting used in the previous NTP studies on RFR exposure. For example, A-weighting represents the relative sensitivity of the human ear, whereas Z-weighting gives equal weight to all frequencies. An Audix TM1 microphone was employed for noise measurement, as it has a frequency response that extends to approximately 30 kHz (Figure A-22, Figure A-23), with a modification of A-weighting at low frequencies of up to 2.5 kHz and Z-weighting modified by the microphone frequency response at high-end frequencies. This extended frequency range was used to address questions raised in the public review of the previous NTP studies related to the hearing range of rodents in the range from 400 Hz to 75 kHz for rats and 900 Hz to 79 kHz for mice. The custom noise measurement was based on two metrics: the average noise level and the peak noise level.

The light sensor was fed from a plastic optical fiber, which was also inserted into the chamber. In each chamber, two E-field probes that were calibrated and traceable to national standards were placed close to the exposure volume.

Figure A-22

Audix TM1 Microphone Used for Noise Measurement

Panel (A) shows the dimensions of the microphone in millimeters. Panel (B) shows the frequency response of the microphone.

Figure A-23

Noise as a Function of Airflow (Fan Speed)

Linked to the sensor pack was a noise generator, which generated “GSM” noise to mask any differences between the chambers. The GSM noise could be selectively employed only during GSM exposures. The noise was amplified to the required level and played back using a Ci130QS (45 Hz–34 kHz) speaker (KEF, Maidstone, United Kingdom) placed outside the chamber, connected via a dedicated 130 × 130 mm honeycomb vent to deliver sound into the chamber.

### A.6.2 Airflow

Airflow through the chamber was measured by means of an F400 series sensor (Degree Controls, Inc, Nashua, NH) as shown in Figure A-24, and the measured velocity was related to the number of air changes per hour. Laminar flow elements were added to the outlet manifold (top right of the chamber) to reduce turbulence in the airflow and to increase measurement accuracy.

Figure A-24

F400 Series Airflow Sensor

According to the measured airflow, the speed of the fans, two at the chamber air inlet and two at the chamber air outlet, could be adjusted using a fan speed controller, with one speed regulator per chamber. The temperature and humidity of the chamber air were essentially the same as those of the air in the exposure room, which were in turn controlled by the facility. As the power dissipated in each of the chambers, the temperature increase in the RF chambers compared to the control chamber was less than 0.1°C.

### A.6.3 Ventilation

The environment in terms of temperature and humidity in the chamber was not controlled by the exposure system but relied on the building control systems. Airflow was maintained at a sufficiently high level to ensure approximately identical conditions in the chamber as in the animal room by virtue of fans integrated into the inlet and outlet plenums.

Ventilation was provided by two Sanyo Denki (Tokyo, Japan) fans on the inlet and two on the air outlet; the air then passed through a honeycomb vent with dimensions of 160 × 340 mm (3/16-inch cell size) to provide RF isolation.

All sensors, including the air speed sensor, were contained in the outlet manifold for circulated air. The cross section of the box was 190 × 360 mm; therefore 1 m/s flow corresponded to 0.068 m^3^/s or approximately 4 m^3^/min. The chamber volume was approximately 2.35 m^3^, hence even the lowest airflows provided much higher turnover than the minimum required by the National Institute of Environmental Health Sciences Division of Translational Toxicology (NIEHS/DTT). Higher airflow was highly desirable for systems fitted with incandescent lighting, to remove the additional heat generated by the lighting and help maintain the chamber temperature consistent with that of the animal room.

### A.6.4 Sensor Summary

The environmental parameters measured are summarized in Table A-2 along with the nominal accuracy where applicable.

Table A-2 Sensors, Ranges, and Accuracy

Sensor | Range | Uncertainty
Airflow | 0.5–10 m/s | 4% + 0.1 m/s
Temperature | −40°C–60°C | ±0.3°C at 20°C
Humidity | 0%–100% | ±2.5% at 20°C
Noise | −30 to 90 dBA | ±1.2 dB
Light | on/off
Vibration | relative dB

The inherent uncertainty associated with the field sensors related to the calibration process includes elements caused by variations in the field within the chamber and the temporal variation caused by the stirrer rotation. By virtue of having two field sensors in each chamber, the effects of chamber homogeneity were mitigated. The contributions to the uncertainty in the measurement of the field at 900 MHz and 1,900 MHz are described in Table A-3 and Table A-4, respectively.

Table A-3 Field Measurement Uncertainty at 900 MHz

Equipment/Factor | Uncertainty Distribution | Divisor × | Coverage | Standard Uncertainty
Absolute Accuracy of the E-field Probe | ±0.26 dB | Normal | 1 | ±0.26 dB
Frequency Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Dynamic Range Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Isotropy | ±0.4 dB | Rectangular | √3 | ±0.12 dB
Field Control | ±0.2 dB | Normal | 1 | ±0.20 dB
Homogeneity | ±0.7 dB | Normal/2 Probes | 1/√2 | ±0.49 dB
Combined Standard Uncertainty | | | | ±0.65 dB

Table A-4 Field Measurement Uncertainty at 1,900 MHz

Equipment/Factor | Uncertainty Distribution | Divisor × | Coverage | Standard Uncertainty
Absolute Accuracy of the E- and H-field Probes | ±0.26 dB | Normal | 1 | ±0.26 dB
Frequency Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Dynamic Range Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Isotropy | ±0.4 dB | Rectangular | √3 | ±0.12 dB
Field Control | ±0.2 dB | Normal | 1 | ±0.20 dB
Homogeneity | ±0.42 dB | Normal/2 Probes | 1√2 | ±0.30 dB
Combined Standard Uncertainty | | | | ±0.53 dB

## A.7 Signal Generation and Amplification

### A.7.1 Signal Generator

The signal generator chosen—Rhode & Schwarz model SMBV-100A with frequency option SMBV-B103 covering 9 kHz–3.2 GHz (Figure A-25)—is extremely flexible and can generate modulations with base bandwidths of up to 120 MHz at carrier frequencies of up to 3.2 GHz. The SMBV-B10/B92 combination in conjunction with the R&SWinIQSIM2 software allowed any arbitrary complex modulation (32 Mbyte) to be generated.

For GSM modulations, internal modulation with one time slot active was used. For IS-95 (i.e., CDMA) systems, internal in-phase and quadrature (I/Q) modulation for offset quadrature phase-shift keying (OQPSK) was used, with a pseudo random modulation stream, a chip rate of 1.228 Mcps, and the cdmaOne (IS-95) baseband filter to produce a baseband constellation and modulated spectrum identical to those of the IS-95 (i.e., CDMA) setup used in the previous NTP studies (Figure A-26).

The Rhode & Schwarz signal generator could also provide modulations such as 3G and 4G signals. 5G signal modulation was expected to be similar to 4G in terms of modulation; however, the carrier frequencies at that time were not known, and it was thought to be outside the design scope of this exposure system. The signal generator supports several modulations, including Third Generation Partnership Project (3GPP) Long-Term Evolution (LTE) Frequency Division Duplex (FDD) and Time Division Duplex (TDD), LTE-Advanced, 3GPP FDD/High-Speed Packet Access (HSPA)/HSPA+, GSM/Enhanced Data rates for GSM Evolution (EDGE)/EDGE Evolution, Time Division-Synchronous CDMA (TD-SCDMA), and Wireless Local-area Network (WLAN).

Figure A-25

Rhode & Schwarz Signal Generator SMBV-100A

Figure A-26

Interim Standard 95 (i.e., CDMA) In-phase and Quadrature (I/Q) Constellation

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

### A.7.2 Amplifier Performance

Figure A-27 shows the amplifiers with the controller. Each amplifier comprised two RF power modules of ≥175 W each combined with integrated circulators. At 900 MHz, the saturated power output of the completed amplifiers was approximately 320 W. The amplifiers had lower output power at 1,900 MHz, with the lowest output power being >200 W.

Figure A-27

Three Amplifiers and the Amplifier Controller

### A.7.3 Amplifier Linearity and Spectral Regrowth

Figure A-28 shows the IS-95 (i.e., CDMA) signal spectrum at the highest expected output power for both 900 and 1,900 MHz; the performance at each frequency was the same within approximately 2 dB. Figure A-29 shows a comparison of the performance of broadband amplifiers in the current study to that achieved in the previous NTP studies with single band amplifiers. The comparison showed that linearity was about the same at 1,900 MHz and slightly worse at 900 MHz. However, all unwanted spectral components were <l/l,000 of the power within the intended bandwidth and at most 5 dB higher than the spectral mask.

Figure A-28

Interim Standard 95 (i.e., CDMA) Spectra for 900 MHz (Blue) and 1,900 MHz (Red)

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

Figure A-29

Comparison of the Interim Standard 95 (i.e., CDMA) Spectra from the Amplifiers

Panel (A) shows the response for 1,900 MHz. Panel (B) shows the response for 900 MHz. Blue indicates the spectra from single band amplifiers used in the National Toxicology Program radiofrequency radiation studies, and red indicates the spectra from broadband amplifiers used in the current studies. The spectral mask limits for Interim Standard 95 CDMA transmissions are denoted by the red, dotted lines on the plots. CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

### A.7.4 Antennas

The antennas were designed to cover both the 900 MHz and 1,900 MHz frequency bands and did not need to be changed when switching from rat exposures at 900 MHz to mouse exposures at 1,900 MHz. Broadband log periodic antennas were designed and custom manufactured to meet the requirements; the maximum dimensions of these antennas were 40 cm long, 20 cm wide, and 2 cm deep. The simulation model and predicted performance are shown in Figure A-30, and the physical antenna is shown in Figure A-31. The high-power chamber had three antennas, the medium-power chamber had three antennas, and the low-power chamber had one antenna, for a total of seven antennas within the system. All antennas were placed such that their main beam was aimed at one of the stirrers to maximize the scattering of the field and avoid direct exposure of the animals. All antennas were placed in the rear of the chamber. In the case of the high- and medium-power chambers, antennas were placed in the top left and bottom right and aimed at the stirrer on the rear wall. The other antenna in the top right was aimed at the stirrer on the ceiling. In the low-power chamber, only the antenna in the top right was installed.

Figure A-30

(A) Log Periodic Antenna Computer-aided Design Model and (B) Reflection Coefficient

Figure A-31

Log Periodic Antenna Installed in One of the Chambers

### A.7.5 Exposure Control

The exposure level in any given chamber depended on (i) the number of amplifiers connected to the chamber, (ii) the output power from the amplifiers, (iii) the number and weight of the animals in the chamber, and (iv) the amount of bedding and feed in each chamber. The number of amplifiers connected to the different chambers depended on which time slot was being used and the required SAR for that chamber. Typically, the first 10-minute time slot had all three amplifiers connected to the high-power chamber (Chamber 1), with each amplifier connected to a different antenna (i.e., the chamber was used as a cavity power combiner). In the second 10-minute slot, two amplifiers were connected to the mediumpower chamber (Chamber 2) and the third amplifier was connected to the low-power chamber (Chamber 3). Therefore, each amplifier’s output power was individually controlled, which was achieved by controlling the input power to each amplifier in each 10-minute time period. The controller facilitated this by varying the input to a set of voltage-controlled attenuators, which in turn set the output power to the required value under computer control. The control level was calculated based on the measured field strength in a given chamber. In addition to the level set by the computer control, further levels of control were integrated. These included a limiter to ensure that the maximum output power level did not exceed the safe operation level for each amplifier and that the maximum reflected power did not exceed the set threshold, as this would increase the dissipation within the amplifier with the potential for permanent damage. The block diagram for the controller is given in Figure A-32. The software generated warnings if the measured fields and calculated SAR deviated from the target by more than a given threshold, to alert staff to a potential problem. To ensure the safety of the animals, the exposure would be aborted if the SAR exceeded a second set of programmable thresholds, which were set in consultation with the testing facility and NIEHS/DTT scientists.

Figure A-32

Radiofrequency Amplifier Level-Control System

## A.8 Chamber Quality Factor and Stirring Performance

### A.8.1 Insertion Loss Measurements

A vector network analyzer (VNA), Agilent 8753B, connected to two antennas in the reverberation chamber was used to characterize the losses due to the individual chamber contents, such as racks, bedding, and feed. These measurements were important for calculation of the power needed to meet the required field strengths in the chambers.

#### A.8.1.1 Measurement Uncertainty

The measurement repeatability was assessed for the VNA S21 measurements using sets of five repeated measurements of 10,025 points (i.e., measurement locations) spaced over 124/125 rotations of the two stirrers. The maximum standard deviation observed at either 900 MHz or 1,900 MHz was 0.05 dB.

The stated uncertainty of the Agilent 8753B transmission measurement assuming a typical insertion loss of 20 dB, a source and load match of −10 dB, and response calibration is 0.8 dB (k = 2). The overall uncertainty for the measurement is summarized in Table A-5.

Table A-5 Overall Uncertainty of the Measurement

Equipment | Uncertainty | Distribution | Divisor × Coverage | Standard Uncertainty
Agilent 8753B | ±0.8 dB | Normal (k = 2) | 2 | ±0.4 dB
Stirrer Modulation | ±0.05 dB | Normal | 1 | ±0.05 dB
Combined Standard Uncertainty | | | | ±0.4 dB

The combined standard uncertainty was 0.4 dB or 9.7% for the S21 and effective quality (Q) values calculated in the following sections. On the basis of the insertion loss measurements for the chamber with each additional element inserted, the following effective Q values were determined for 900 MHz and 1,900 MHz. The overall Q value for any combination of elements can be calculated with the following expression:

[formula image]

The equivalent Q values of elements in the empty and fully loaded reverberation chambers are given in Table A-6 and Table A-7, respectively. The measured S-parameters are shown in Figure A-33 and Figure A-34. For correct operation of a reverberation chamber, the points in the plots, which correspond to discrete stirrer positions, should be equally distributed across all four quadrants of the S21 (transmission between two antennas in a single chamber) plots, as any bias in a given direction would indicate the presence of unstirred energy, which would degrade the homogeneity of the exposure. In addition, analysis of the magnitude of S21 allows information on the Q factor of the chamber to be determined. The equivalent Q values of components in the fully loaded reverberation chamber are summarized in Table A-8.

Table A-6 Equivalent Q Values of Elements in the Empty Reverberation Chamber

Empty Chamber | 900 MHz | 1,900 MHz
Quality Factor | 1,121 | 1,624
Stirred to Unstirred Energy | 9.7 dB | 14.2 dB
Average Reflection Coefficient | −8.3 dB | −12.2 dB

Table A-7 Equivalent Q Values of Elements in the Fully Loaded Reverberation Chamber

Fully Loaded Chamber | 900 MHz | 1,900 MHz
Quality Factor | 157 | 385
Stirred to Unstirred Energy | 24.1 dB | 14.5 dB
Average Reflection Coefficient | −11.4 dB | −17.0 dB

Figure A-33

900 MHz S-Parameter Plots

Figure A-34

1,900 MHz S-Parameter Plots

Table A-8 Equivalent Q Values of Components in the Fully Loaded Reverberation Chamber

Component | 900 MHz | 1,900 MHz
Empty Chamber | 1,121 | 1,624
Racks | 1,072 | 1,029
Cages | 17,117 | 6,859
Bedding | 1,331 | 2,517
Feed | 6,667 | 9,649
Phantoms | 268 | 2,752

The following expression from the NIST Technical Note 1506^42^ allows the Q value to be related to input power and field strength:

[formula image]

On the basis of the Q values evaluated, the relative power absorptions obtained for 10 rats and 10 mice with assumed maximum weights of 550 g/rat at 900 MHz and 55 g/mouse at 1,900 MHz, respectively, are listed in Table A-9.

Table A-9 Relative Power Absorptions for Ten Rats and Ten Mice

Element | Power Dissipation^a^
Element | 900 MHz | 1,900 MHz
Chamber Walls, Lights, Stirrers | 13.7% | 23.7%
Racks | 14.3% | 37.4%
Cages | 0.9% | 5.6%
Bedding | 11.5% | 15.3%
Feed | 2.3% | 4.0%
Phantoms | 57.3% | 14.0%

^a^ Obtained assuming a maximum weight for rats of 550 g/rat and a maximum weight for mice of 55 g/mouse.

On the basis of the Q values evaluated, the power requirements for 10 rats and 10 mice with maximum weights of 550 g and 55 g, respectively, are listed in Table A-10. The maximum efficiency is 57% for rats and 14% for mice.

Table A-10 Power Requirements for Ten Rats and Ten Mice

| Maximum SAR | Power Absorbed by Animal | Average Power Delivered to Chamber | Peak Power Delivered to Chamber
Rats^a^ | 8 W/kg | 44 W | 77 W | 640 W
Mice^b^ | 15 W/kg | 8.25 W | 59 W | 490 W

^a^ Obtained assuming a maximum weight for rats of 550 g/rat.

^b^ Obtained assuming a maximum weight for mice of 55 g/mouse.

## A.9 Field Uniformity Measurement

### A.9.1 Measurement Uncertainty

The requirements for field uniformity form a key element of the specification of the chamber, and a large number of measurements must be made over the working volume, both with the chamber empty and fully loaded with racks and phantoms, to assess the uniformity. Unlike VNA S-parameter measurements, field measurements are time consuming. Thus, two elements of the measurement were assessed, namely, the measurement repeatability and the increase in uncertainty as the number of points (i.e., measurement locations) is reduced and the measurement speed is increased.

The repeatability was assessed on the basis of 3,440 stirrer positions over 4/5 rotations of the two stirrers. The standard deviation of sets of 900 MHz measurements was <0.2 dB for the total field and 0.3 dB for any given component of the field. The standard deviation of the sets of 1,900 MHz measurements was 0.22 dB for the total field and 0.37 dB for any given orthogonal field component. The overall uncertainty for the field strength measurements was calculated from the individual uncertainty elements as shown in Table A-11.

Table A-11 Standard Uncertainty in Measurements of E-fields and H-fields

Equipment | Uncertainty | Distribution | Divisor × Coverage | Standard Uncertainty
Absolute Accuracy of the E- and H-field Probes | ±0.26 dB | Normal | 1 | ±0.26 dB
Frequency Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Dynamic Range Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Isotropy | ±0.4 dB | Rectangular | √3 | ±0.12 dB
Stirrer Modulation/ Repeatability | ±0.22 dB | Normal | 1 | ±0.22 dB
Combined Standard Uncertainty | | | | ±0.40 dB

### A.9.2 Homogeneity Measurements

The measurements were performed on a grid ΔX = 150 mm, ΔY = 95 mm, and ΔZ = 135 mm with 12 measurement locations inside each cage apart from two areas close to the fixed probes integrated into each chamber where only six measurement locations could be measured.

The homogeneity measurement was performed with six EF3DV3 E-field probes (SPEAG, Switzerland) supported by Rohacell (ε_r_ ≈ 1.1) inside a modified cage with parts close to the probe tips removed (Figure A-35). The jig was placed in the chamber facing forward and rearward to measure all 12 locations (Figure A-36). When the data acquisition electronics (DAE) units were at the rear, the lower shelves had to be removed to allow access.

Figure A-35

Measurement Jig in a Modified Cage with Six E-field Probes

Figure A-36

Measurement Jig, (A) Forward-facing and (B) Rearward-facing

For homogeneity with the chamber loaded with phantoms, one cage was removed to allow the probe jig to be inserted. It was inserted only from the front, as there was no space for the optical connections when all shelves were present, which prevented the use of rear-facing DAE configurations (Figure A-37).

Figure A-37

Chamber Loaded with Rat Phantoms, One Cage Removed to Allow Probes to Be Inserted

Measurements were normalized with respect to the field measured by the integrated E-field probes to account for variations in the field with time. The field samples were obtained over a 2-minute period at each location and involved an integral number of stirrer rotations, namely, five for the top stirrer and seven for the rear stirrer. The field was sampled continuously over this period.

#### A.9.2.1 Homogeneity – 900 MHz

Table A-12 Empty Chamber, 108 Measurement Locations

| E_X_ | E_Y_ | E_Z_ | E_Total_ | E_X,Y,Z_
Average (dB) | −0.44 | −0.54 | −0.23 | −0.40 | −0.40
StDev (dB) | 1.27 | 1.34 | 0.80 | 0.73 | 1.16
Min (dB) | −3.36 | −4.68 | −2.54 | −1.50 | −4.82
Max (dB) | 2.72 | 3.22 | 2.53 | 1.78 | 3.08

Table A-13 Loaded Chamber, 60 Measurement Locations

| E_X_ | E_Y_ | E_Z_ | E_Total_ | E_X, Y, Z_
Average (dB) | −0.21 | −0.05 | 0.17 | −0.03 | −0.03
StDev (dB) | 1.43 | 1.31 | 1.01 | 0.84 | 1.26
Min (dB) | −5.85 | −3.90 | −3.21 | −2.17 | −6.03
Max (dB) | 3.55 | 2.84 | 2.81 | 2.06 | 3.37

For the empty chamber (Table A-12), the key figures were:

- Homogeneity = 0.73 dB
- Isotropy = 1.16 dB
- All measurement locations within ±2.5 dB

For the loaded chamber (Table A-13), the key figures were:

- Homogeneity = 0.84 dB
- Isotropy = 1.26 dB

Field maps were evaluated at 900 MHz over three vertical planes at rear, middle, and front locations in the cages, for the empty chamber without cages, bedding, and phantoms. For the locations that could not be measured, average fields were substituted. Figure A-38, Figure A-39, and Figure A-40 show the contours at the rear, middle, and front planes, respectively.

Figure A-38

Rear Plane at Y = 0 mm – 900 MHz

Colored contours in the figure show the directed components of the E-field (X-Component, Y-Component, and Z-Component, or Ex, Ey, and Ez), and total E-field (Et) in dBV/m in the plots from left to right. Axes show distance in millimeters.

Figure A-39

Middle Plane at Y = 95 mm – 900 MHz

Colored contours in the figure show the directed components of the E-field (X-Component, Y-Component, and Z-Component, or Ex, Ey, and Ez), and total E-field (Et) in dBV/m in the plots from left to right. Axes show distance in millimeters.

Figure A-40

Front Plane at Y = 190 mm – 900 MHz

Colored contours in the figure show the directed components of the E-field (X-Component, Y-Component, and Z-Component, or Ex, Ey, and Ez), and total E-field (Et) in dBV/m in the plots from left to right. Axes show distance in millimeters.

#### A.9.2.2 Homogeneity – 1,900 MHz

Table A-14 Empty Chamber, 108 Measurement Locations

| E_X_ | E_Y_ | E_Z_ | E_Total_ | E_X,Y,Z_
Average (dB) | 0.35 | 0.55 | 0.35 | 0.42 | 0.42
StDev (dB) | 0.62 | 0.66 | 0.68 | 0.44 | 0.66
Min (dB) | −1.34 | −1.44 | −2.10 | −0.94 | −2.17
Max (dB) | 1.82 | 1.73 | 1.99 | 1.18 | 1.92

Table A-15 Loaded Chamber, 60 Measurement Locations

| E_X_ | E_Y_ | E_Z_ | E_Total_ | E_X,Y,Z_
Average (dB) | 0.19 | 0.32 | −0.26 | 0.09 | 0.09
StDev (dB) | 0.70 | 0.81 | 0.81 | 0.60 | 0.80
Min (dB) | −1.55 | −1.78 | −1.95 | −1.23 | −2.30
Max (dB) | 1.62 | 2.36 | 2.27 | 1.79 | 2.59

For the empty chamber (Table A-14), the key figures were:

- Homogeneity = 0.44 dB
- Isotropy = 0.66 dB
- All measurement locations within ± 1.2 dB

For the loaded chamber (Table A-15), the key figures were:

- Homogeneity = 0.60 dB
- Isotropy = 0.80 dB

Field maps were evaluated at 1,900 MHz over three vertical planes at rear, middle, and front locations in the cages, for the empty chamber without cages, bedding, and phantoms. For the locations that could not be measured, average fields were substituted. Figure A-41, Figure A-42, and Figure A-43 show the contours at the rear, middle, and front planes, respectively.

Figure A-41

Rear Plane at Y = 0 mm – 1,900 MHz

Colored contours in the figure show the directed components of the E-field (X-Component, Y-Component, and Z-Component, or Ex, Ey, and Ez), and total E-field (Et) in dBV/m in the plots from left to right. Axes show distance in millimeters.

Figure A-42

Middle Plane at Y = 95 mm – 1,900 MHz

Colored contours in the figure show the directed components of the E-field (X-Component, Y-Component, and Z-Component, or Ex, Ey, and Ez), and total E-field (Et) in dBV/m in the plots from left to right. Axes show distance in millimeters.

Figure A-43

Front Plane at Y = 190 mm – 1,900 MHz

Colored contours in the figure show the directed components of the E-field (X-Component, Y-Component, and Z-Component, or Ex, Ey, and Ez), and total E-field (Et) in dBV/m in the plots from left to right. Axes show distance in millimeters.

## A.10 Stirrer Modulation

The aim of these NIEHS/DTT studies was to mimic mobile handset-like exposure conditions inside the reverberation chambers, as in the previous NTP studies. The modulation of the RF carrier is one element; the second is how the output power of a handset varies within the communication network. In these studies, one of two different digital cellular communication signals (GSM and IS-95 CDMA) was applied within the chambers. This section includes the rationales for the signal concepts and proposed methodologies to achieve exposure conditions inside the chambers that could mimic the real-life power control variations.

### A.10.1 GSM Mobile Station Signal

The signal from GSM mobile handsets is mainly determined by the multiple access method applied. GSM facilitates both frequency division multiple access (FDMA) and time division multiple access (TDMA). For FDMA, the GSM band is divided into channels 200 kHz wide. As a complement to FDMA, a TDMA mechanism enables up to eight time slots (voice channels) per frequency channel (i.e., a mobile handset transmits in only one out of eight available channels during a voice communication), which introduces a pulsed signal shape with a pulse repetition rate of 217 Hz. Such a TDMA frame has a length of 4.6 ms, and 26 TDMA frames make up a multiframe with a 120 ms duration. During a multiframe, a mobile handset transmits in 25 out of 26 possible time slots. This TDMA frame structure causes significant lowfrequency components to be superimposed on the RF carrier at 8.3 and 217 Hz. In GSM, the duplexing between the uplink (handset transmits to the base station) and downlink (base station transmits to the handset) is implemented in the frequency and time domains, and the frequency spacing between uplink and downlink frequencies is kept constant. The downlink frequency is chosen according to the cell (i.e., the area covered by a base station into which the mobile handset is allocated). To minimize interference between neighboring cells, a frequency reuse policy is applied. This policy implies that when a mobile handset is handed over (i.e., moves from one cell to another), the frequencies in the uplink and downlink change, and the transmit frequency changes. The power levels after power control signal from the base station exhibit a stepwise response. The power control has a dynamic range of 30 dB subdivided into 2 dB power level steps. The power control is typically implemented by means of a slow associated-control channel, which facilitates a power-control update rate no faster than every four multiframes (i.e., every 480 ms). Once a target power level is received, the mobile station is able to regulate its power in 2 dB steps every 60 ms (i.e., a power regulation over 15 steps [full dynamic range] takes 900 ms). GSM base stations, however, typically average the received signal strength from a mobile handset over 1 s, such that the actual power regulation usually takes place after multiples of 480 ms.

In summary, the main extremely low-frequency (ELF) component of the GSM system is composed of a 217 Hz TDMA frame, 8.3 Hz multiframe, 2 Hz discontinuous transmission (DTx), and <1 Hz power control.

### A.10.2 Interim Standard 95 (i.e., CDMA) Mobile Station Signal

IS-95 (also known as TIA-EIA-95) is the first CDMA-based digital cellular communication standard. The system’s multiple access is based entirely on code division separation of mobile stations as well as base stations, which implies that the signal structure is significantly different from that of GSM. In the forward downlink, a set of 64 Walsh codes, which are deterministic and orthogonal, are applied to spread and separate the individual channels in the downlink of a cell. After orthogonal spreading, a short 16-bit pseudo noise (PN) code is applied to further spread the signal and identify the cell. Hence, separation of neighboring cells in the frequency domain is no longer necessary.

Eventually, there is no need for the mobile station to change its transmission frequency during the transition from one cell to another. Since Walsh codes require a synchronous system in the reverse uplink, only long 42-bit PN codes are applied. As with GSM, duplexing between the forward and reverse links is implemented in the frequency domain. In CDMA systems, efficient power control is crucial. Because all mobile stations transmit and interfere in the same frequency channel, each mobile decreases the signal to noise ratio of all the other mobiles. Hence, the output power of a mobile handset should be kept to the minimum level that guarantees good voice quality. On the other hand, when moving around, the mobile handset is subject to slow and fast fading, shadowing, and external interferences. To keep the output power low and compensate for the effects of changing communication channel loss, fast power control is necessary. When an IS-95 (i.e., CDMA) mobile station is actively communicating, a closed-loop power control is applied. The base station monitors the signal quality in the reverse link and inserts power control bits in the communication channel, which facilitates power control over a dynamic range of 48 dB in 1 dB steps with an update rate of 800 Hz. The power control is implemented by sending a binary value of 1 to regulate the transmit power by 1 dB down and a value of 0 to regulate the transmit power by 1 dB up. A quasi-static power level is therefore implemented with an alternating 0101 power control pattern.

### A.10.3 Mobile Station Signals in Real Networks

To determine the time-domain signal behavior (i.e., the ELF components from the power control and frame structure superimposed on the RF carrier), mobile stations in real networks were evaluated. The System Network and Handset Analyzer (SYNEHA; Figure A-44) was used to evaluate mobile stations in real networks. The mobile system measures the output power of mobile phones attached to phantom heads while moving through a cellular network. The system is able to measure variations in mobile phone output power at rates of up to 2 kHz.

Figure A-44

System Network and Handset Analyzer

(A) Phantom heads with mobile phones and System Network and Handset Analyzer (SYNEHA) data acquisition system mounted inside the measurement vehicle. (B) Block diagram of the SYNEHA measurements system. Examples shown are the two specific anthropomorphic mannequin phantom heads with mobile phone handsets (HS) attached to each ear. The field sensors (FS) measure the E-field inside the phantom. This field is analog-to-digital converted and optically forwarded by the data acquisition electronics (DAE). The Exposure Acquisition System (EASY4) is used as a data logger for the field values. The personal computer (PC) controls the system and stores the field and position data. Figure adapted from Capstick et al.^17^ UPS = uninterruptible power supply; GPS = global positioning system.

In Figure A-45, the ELF components resulting from a GSM mobile phone moving through a highway and an urban environment are shown. Despite the different environments, significant low-frequency components resulting from the access scheme (time slots and data frames) and handovers can be identified at 8.3 Hz (multiframe) as well as in the sub-Hz range. In contrast to GSM, in IS-95 (i.e., CDMA), no such significant components can be identified in the ELF spectrum moving through suburban environments (Figure A-46).

Figure A-45

GSM Extremely Low-Frequency Components in Urban and Highway Environments

Figure adapted from Capstick et al.^17^ GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation.

Figure A-46

Interim Standard 95 (i.e., CDMA) Extremely Low-Frequency Components in Suburban Environments

Figure adapted from Capstick et al.^17^ CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

### A.10.4 Signals in the Experiment

In the experiment, the GSM and IS-95 (i.e., CDMA) signals provided by the signal generators represent a standard voice call with a PN data sequence being transmitted. To also mimic the ELF components of GSM and IS-95 (i.e., CDMA) mobile phones in a real network, the appropriate stirrer speeds were determined. The time-domain field variations of a continuous wave (CW) signal applied to the fully loaded chamber were measured with an antenna placed in the chamber. Time-domain sampling was performed over a period of 60 or 120 s with a diode detector and a digital oscilloscope to allow an integral number of stirrer rotations to be sampled. The detector voltages were then converted to powers, and fast Fourier transform was performed to obtain the frequency domain low-frequency power distribution of the stirrer modulation. Many combinations of stirrer speeds were measured, and those that best represented the ELF components because of power control were selected for the exposure experiments. The chosen stirrer speeds shown in Table A-16 indicate the figures corresponding to the resulting spectra.

Table A-16 Horizontal and Vertical Stirrer Speed Combinations for GSM and IS-95 (i.e., CDMA) Modulation

Frequency | Modulation | Horizontal (rpm) | Vertical (rpm) | Figure
900 MHz | GSM | 6.0 | 4.0 | Figure A-47
900 MHz | IS-95 CDMA | 7.0 | 9.0 | Figure A-48
1,900 MHz | GSM | 2.85 | 5.70 | Figure A-49
1,900 MHz | IS-95 CDMA | 4.5 | 5.0 | Figure A-50

GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation; IS-95 = International Standard 95; CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

Figure A-47

900 MHz GSM

GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation.

Figure A-48

900 MHz Interim Standard 95 (i.e., CDMA)

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

Figure A-49

1,900 MHz GSM

GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation.

Figure A-50

1,900 MHz Interim Standard 95 (i.e., CDMA)

CDMA = Code Division Multiple Access-modulated cell phone radiofrequency radiation.

## A.11 Dosimetry

Dosimetry in the fields of health physics and radiation protection is the measurement, calculation and assessment of internal exposure to the body. Nonionizing radiation dosimetry within the RF range is quantified as the SAR. The SAR is expressed in W/kg body weight (W/kg). It is not possible to measure induced fields or SAR directly in a subject (humans or animals); thus, the electromagnetic fields that a subject is exposed to are measured and numerical simulations using different postures of anatomical models are performed representing different species, sexes, and age groups (numerical dosimetry). If the incident field is well characterized, the correlation between incident field conditions and the fields induced in the different tissues and organs can be established. However, the correlation needs to be verified experimentally using homogeneous phantoms (experimental dosimetry).

The numerical dosimetry for both rats and mice was reported in Gong et al.^18^ and relates to the SAR induced in the bodies (whole-body and tissue specific) for a given incident field strength within a reverberation chamber environment as a function of the animal’s body weight (Figure A-51).

Figure A-51

Specific Absorption Rate Sensitivity for Rats at 900 MHz and Mice at 1,900 MHz as a Function of Body Weight Based on Numerical Dosimetry Using Anatomical Models

Figure adapted from Gong et al.^18^ SAR = specific absorption rate.

### A.11.1 Experimental Dosimetry Phantoms

Experimental dosimetry was performed in the study chambers using the control system designed and fabricated for these studies. During system testing, animal surrogates, or “phantoms” were used. Each phantom consisted of a container with a low-dielectric-constant, low-loss material filled with an appropriate volume of tissue-simulating liquid. The appropriate tissue-simulating liquid was selected following simulations of the whole-body average SAR (SAR_WB_) efficiency achieved with liquids of varying dielectric constants and loss tangents compared to that of the actual full anatomical body model of the animal with the same weight.

Simulations of full anatomical models of the rat or mouse provided the SAR distribution across all tissues, which was then averaged to provide the overall average SAR. The overall average SAR was then normalized to an incident field strength of 1 V/m to provide the SAR_WB_ sensitivity. Simulations of the phantoms filled with a selection of tissue-simulating liquids were performed, and the tissue-simulating liquid that provided the closest average SAR value was selected. The chosen liquids were not meant to represent the average tissue properties of a rat or mouse but to represent the same absorption, which is related not only to individual tissue properties within the anatomical model but also the inhomogeneous field distribution.

For the male rats, a nominal 0.5 L bottle filled to the top with approximately 550 mL tissue-simulating liquid was used for the male rat phantom. The specific tissue-simulating liquid used for the rat was head-simulating liquid (HSL) 900 (SPEAG, Switzerland), with properties ε_r_ = 41.5, σ = 0.97 S/m, which provided a good match to the whole-body anatomical rat. Figure A-52 shows the physical rat phantom and the corresponding model used for numerical dosimetry.

Figure A-52

(A) Rat Phantom and (B) SEMCAD Model of the Rat Phantom

From the simulations, the average SAR_WB_ efficiency could be determined. Figure A-53 illustrates the SAR distribution induced by the isotropic field from which the whole-body average was calculated and the SAR efficiency determined. For the male rat phantom filled with 550 mL HSL900, the SAR_WB_ efficiency was 5.556 × 10^−5^ (W/kg)/(V^2^/m^2^).

Figure A-53

Male Rat Phantom Specific Absorption Rate Distribution

For the physical mouse phantom, a nominal 50 mL conical centrifuge tube filled to the top with 55 mL of HSL1900 (SPEAG, Switzerland) was used. HSL1900 is the tissue-simulating liquid, with properties ε_r_ = 40.0, σ = 1.40 S/m, that provided the best match to the SAR_WB_ efficiency of the mouse. The average SAR_WB_ efficiency for the mouse phantom was 1.50 × 10^−4^ (W/kg)/(V^2^/m^2^).

Figure A-54 shows the physical mouse phantom, the corresponding SEMCAD model, and the simulated SAR distribution in the phantom.

Figure A-54

(A) Mouse Phantom, (B) Sim4Life Phantom Model, and (C) Simulated Specific Absorption Rate Distribution in the Phantom

### A.11.2 Temperature Method

The SAR in the animal phantoms was assessed experimentally using the temperature method. In this method, animal phantoms were exposed to RFR in a chamber while the temperature of the liquid was monitored. When a liquid phantom was exposed to RF, the temperature change was measured during the applied RFR (i.e., the heating phase), and after RF was switched off (i.e., the cooling phase), and the heat transfer time constant τ was determined. By applying the lumped-heat-capacity method described in Heat Transfer,^19^ the liquid temperature follows the differential equation below, based on cooling to the ambient temperature of the environment and RF heating, encompassing a cooling term due to heat loss to the environment and a heating term due to power absorption:

[formula image]

where C_liquid_ is the heat capacity of the tissue-simulating liquid, T is temperature, t is time, τ is the time constant, and ΔT is the temperature increase in the liquid (i.e., T_liquid_ − T_ambient_). Two processes are possible: (1) when RF is on, the liquid temperature increases until an equilibrium state is reached, whereby the rate of heat absorbed due to the RF exposure and the rate of heat loss due to convection are equal; (2) when RF is off, the liquid cools through heat convection toward the lower temperature of the environment. SAR values were determined by solving the differential equation for long exposure times (t >> τ) of the heating curve equation when the system is in an equilibrium temperature state:

where C_liquid_ is the heat capacity of the tissue-simulating liquid, τ is the time constant, and ΔT is the temperature increase in the liquid. The determination of SAR_WB_ requires that the temperature of the environment remains constant, coupled with measurements of the absolute temperature of the dummy liquid, measurements of the room temperature, and determination of the time constant τ. The latter was determined by fitting the theoretical curve to the recorded temperature change in the dummy liquid during the heating process.

The time constant of the process can be calculated from either the heating or cooling curve; however, the RF power during the warm-up phase of the power amplifiers can vary by several dB, resulting in increased uncertainty. Consequently, use of the cooling curve is preferred. The stated uncertainty of the temperature probes used in these measurements is ±0.2°C.

### A.11.3 Verification of Rat Dosimetry

The 10 male rat phantoms were placed in cages and positioned in the chamber. Two phantoms were equipped with fixed temperature sensors to evaluate the heating and cooling time constants, Figure A-55 and Figure A-56. The target field strength was set to 400 V/m. The E-field strength, air temperature, and phantom temperature were recorded during the course of the dosimetry. To ensure that the ambient temperature did not change significantly, air was circulated through the chamber and cooler outside air let into the room periodically.

Figure A-55

Rat Phantom with Temperature Sensor

Figure A-56

Typical Rat Phantom (Phantoms P1 and P2) Heating and Cooling Curves

Figure shows ΔT as a function of time and ambient air temperature at two locations.

The SAR uniformity was determined by measuring the phantoms immediately after the power was shut off in as short a time as possible. The cooling of the phantoms was corrected via reference to the phantom(s) using fixed temperature probes that were present throughout the experiment. The data in Table A-17 show excellent agreement—a difference of about 0.36 dB—between the SAR calculated from the field strength present and the SAR measured.

Table A-17 Rat Dosimetry: Comparison of Calculated and Measured Specific Absorption Rate

Rat Dosimetry | Value
Calculated SAR
E-field (V/m) | 402.25
SAR Efficiency ((W/kg)/(V^2^/m^2^)) | 5.56 × 10^−5^
SAR (mW/mL) | 8.99
Measured SAR
CW (J/kg*K) | 3,766
ΔT (°C) | 15.97
τ (s) | 7,169
SAR (mW/g) | 8.28
Difference in SAR (dB) | −0.36

SAR = specific absorption rate.

The uniformity in the male rat phantoms was assessed in the eight phantoms without fixed temperature sensors by measuring the final temperature. The uniformity (standard deviation) in the SAR was 0.36 dB and was within ±0.6 dB of the mean with all phantoms.

#### A.11.3.1 900 MHz Dosimetry Uncertainty

The uncertainty for the rat dosimetry (Table A-18) was based on the values provided for the measurement instrumentation and observed variations in room temperature and time constant.

Table A-18 Uncertainty in the Rat Dosimetry

Equipment/Factor | Uncertainty Distribution | Divisor × | Coverage | Standard Uncertainty
Absolute Accuracy of the E- and H-field Probe | ±0.26 dB | Normal | 1 | ±0.26 dB
Frequency Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Dynamic Range Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Isotropy | ±0.4 dB | Rectangular | √3 | ±0.12 dB
Temperature Probe Accuracy | ±0.05°C | Normal | 1 | ±0.02 dB
Room Temperature Fluctuations | ±0.12 dB | Normal | 1 | ±0.12 dB
Field Control | ±0.2 dB | Normal | 1 | ±0.20 dB
Time Constant Uncertainty | ±0.12 dB | Normal | 1 | ±0.12 dB
Combined Standard Uncertainty | | | | ±0.47 dB

### A.11.4 Verification of Mouse Dosimetry

Ten mouse phantom positions within the chamber were measured using two phantoms with temperature sensors installed (Figure A-57). The temperature was monitored to determine when it approached a constant value at each location, before the phantoms were moved to the next location, which was repeated five times to get 10 positions (i.e., one position in each cage). The final temperature was determined by fitting the “best fit” theoretical curve to each portion of the temperature curves. The time constant was determined from the cooling curve (Figure A-58).

Figure A-57

Mouse Phantoms with Temperature Sensors

Figure A-58

Mouse Phantoms (Phantoms P1 and P2) and Air Temperature Plots

Figure shows ΔT as a function of time and ambient air temperature at ten locations using two phantoms.

The SAR uniformity was determined by measuring and estimating the final temperatures of all phantoms. The cooling time constant was then used to calculate the SAR with temperature probes present throughout the experiment. The data in Table A-19 show excellent agreement—a difference of about 0.2 dB—between the SAR calculated from the field strength present and the SAR measured.

Table A-19 Mouse Dosimetry: Comparison of Calculated and Measured Specific Absorption Rate

Mouse Dosimetry | Value
Calculated SAR
E-field (V/m) | 301
SAR Efficiency ((W/kg)/(V^2^/m^2^)) | 1.50 × 10^−4^
SAR (mW/g) | 13.58
Measured SAR
CW (J/kg*K) | 3,767
ΔT (°C) | 9.52
τ (s) | 2,526
SAR (mW/mL) | 14.19
Difference in SAR (dB) | 0.18

SAR = specific absorption rate.

The uniformity (standard deviation) in the SAR was 0.5 dB and within ±0.9 dB of the mean with all phantoms. Hence, the uniformity for the mouse is also considered excellent.

#### A.11.4.1 1,900 MHz Dosimetry Uncertainty

The uncertainty in the mouse dosimetry (Table A-20) is based on the values provided for the measurement instrumentation and observed variations in room temperature and time constant.

Table A-20 Uncertainty in the Mouse Dosimetry

Equipment/Factor | Uncertainty Distribution | Divisor × | Coverage | Standard Uncertainty
Absolute Accuracy of the E- and H-field Probe | ±0.26 dB | Normal | 1 | ±0.26 dB
Frequency Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Dynamic Range Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Isotropy | ±0.4 dB | Rectangular | √3 | ±0.12 dB
Temperature Probe Accuracy | ±0.05°C | Normal | 1 | ±0.02 dB
Room Temperature Fluctuations | ±0.34 dB | Normal | 1 | ±0.34 dB
Field Control | ±0.2 dB | Normal | 1 | ±0.20 dB
Time Constant Uncertainty | ±0.21 dB | Normal | 1 | ±0.21 dB
Combined Standard Uncertainty | | | | ±0.59 dB

### A.11.5 Verification of the Effect of the Water System on the Dosimetry

The fields around the water system were measured with respect to the fields measured by the two fixed probes in the chamber (Figure A-59).

Figure A-59

Field Probe Arrangement

At 900 MHz, the field strength at the lixit was well below the nominal chamber field strength, showing that the rats would be safe (i.e., that exposure would not be higher than the target SAR) while drinking (Table A-21). The field at the flange was slightly above that of the nominal field but within the variation measured during the homogeneity measurement of the empty chamber, which was up to 3 dB higher than the average field strength.

Table A-21 E-fields Determined at 900 MHz

E_average_ | Flange | Lixit
245 V/m | 279 V/m | 177 V/m
| 1.1 dB | −2.8 dB

Similarly, at 1,900 MHz, the field strength at the lixit was well below the nominal chamber field strength, showing that the mice would be safe (i.e., that exposure would not be higher than the target SAR) while drinking (Table A-22). The field strength at the flange was also lower than that of the nominal field but within the variation measured during the homogeneity measurement within the empty chamber, which was as much as 2.1 dB lower than the average field strength.

Table A-22 E-fields Determined at 1,900 MHz

E_average_ | Flange | Lixit
283 V/m | 265 V/m | 149 V/m
| −0.6 dB | −5.6 dB

In summary, variations in the field strength close to the periphery of the flange on the choke tube—at 1.1 and 0.6 dB with respect to the fixed probes—were well within the variations seen in the empty chamber for both frequencies, 900 MHz and 1,900 MHz. The field strength close to the lixit was always reduced compared to the field strength in the chamber, indicating that the animals would be protected during drinking. The measurement uncertainty is the same as that for the chamber homogeneity (i.e., 0.4 dB).

#### A.11.5.1 Water System Numerical Dosimetry

The water system employed inside the chambers was based on that used in the previous NTP studies as well as on a system designed by the IT’IS Foundation and developed as part of a European project for use in small desktop chambers. However, as this configuration was new, both numerical and experimental dosimetry were performed using the same methods as employed in the previous NTP studies. Simulations were performed using the FDTD solver in SIM4LIFE (Zurich MedTech, Zürich, Switzerland), using anatomical rat and mouse models from the Virtual Zoo (IT’IS Foundation, Zürich, Switzerland). To determine the potential influence of the water system, results were compared for the rat or mouse drinking from and in the absence of the lixit structure. The scope of the numerical dosimetry was extended to elicit information on the frequency bands over which the water system could be expected to perform safely. The frequency responses for the mouse and rat are shown in Figure A-60 and Figure A-61, respectively. The response bandwidth for the rat water system was much narrower than that of the mouse system and more sensitive to all variations in dimension and posture; hence, operation at frequencies other than that intended was not recommended. The response bandwidth for the mouse water system is broader band, and the system could be operated over the frequency range of 1.8 to 2 GHz. Figure A-62 and Figure A-63 show the details of the SAR distributions from the simulations in the center slice at the center frequency of operation for the mouse and the rat, respectively. The SAR scales are the same throughout, with a scale of 0 to −25 dB, where 0 dB = 1 mW/kg for the field strength of a peak at 1 V/m.

Figure A-60

Variation in the Peak Specific Absorption Rate in the Mouse When Drinking as a Function of Frequency

Figure shows the variation when the mouse was alone without a lixit water system (blue, dashed line) and when the mouse was touching the lixit water system (orange, solid line). SAR = specific absorption rate.

Figure A-61

Variation in the Peak Specific Absorption Rate in the Rat When Drinking as a Function of Frequency

Figure shows the variation when the rat was alone without a lixit water system (blue, dashed line) and when the rat was touching the lixit water system (orange, solid line). SAR = specific absorption rate.

Figure A-62

Simulated Specific Absorption Rate Distributions in the Center Slice of the Mouse for Different Locations with Respect to the Water System

(A) Mouse alone. (B) Mouse drinking. (C) Mouse 10 mm from the water system. Scale is in dB relative to the peak specific absorption rate.

Figure A-63

Simulated Specific Absorption Rate Distributions in the Center Slice of the Rat for Different Locations with Respect to the Water System

(A) Rat alone. (B) Rat drinking. (C) Rat 10 mm from the water system. Scale is in dB relative to the peak specific absorption rate.

#### A.11.5.2 Water System Experimental Dosimetry: SAR in Gel Phantoms, Touching and Away from the Water System

Gel phantoms were made to assess the SAR when drinking and well away from the water system for rats at 900 MHz and mice at 1,900 MHz. The relative magnitude of the SAR was determined by observing the rate of temperature change at different locations within the phantom, namely, at the mouth, the head, and the center of the body. A 3D printed shell based on the anatomical models used for the numerical dosimetry was utilized for the rat, whereas a simplified shape was used for the mouse. Evaporation from the exposed gel surface was found to be a confounding process that could reduce the temperature increase at the mouth if the surface was not covered by a plastic membrane. For 900 MHz, the phantom can be seen in Figure A-64 with a close up of the mouth parts touching the lixit.

Figure A-64

Gel Rat Phantom

Panel (A) shows a detailed view of the rat phantom touching the lixit. Panel (B) shows a wide view of the reverberation chamber with the rat phantom touching the lixit.

The results of the rat water system dosimetry can be seen in Table A-23, showing that the SAR in the mouth and head were lower than in the case when the animal is not close to the water system (approximately 100 mm away) and confirming that the animal would be safe (i.e., that the exposure when the animal was drinking water was not higher than the target SAR).

Table A-23 Dosimetry of the Rat Water System

| SAR (mK/s) | | Relative SAR
| Touching Lixit | Not Touching Lixit | Touching Lixit | Not Touching Lixit
Body | 4.58 | 3.90 | 1.00 | 1.00
Head | 2.51 | 4.84 | 0.55 | 1.24
Mouth | 2.27 | 1.92 | 0.50 | 0.49

The gel mouse phantom used for dosimetry at 1,900 MHz is shown in Figure A-65.

Figure A-65

Gel Mouse Phantom

Panel (A) shows a detailed view of the mouse phantom. Panel (B) shows a wide view of the reverberation chamber with the mouse phantom touching the lixit.

The results for the mouse dosimetry are presented in Table A-24, which shows that the SAR in the head was the same as when the animal is not close to the water system. The mouth shows a small increase, although the SAR is lower than that in the head. Despite this small increase in the SAR, it is clear that the increase would not be sufficient to cause RF burns or other detrimental effects.

Table A-24 Dosimetry of the Mouse Water System

| SAR (mK/s) | | Relative SAR
| Touching Lixit | Not Touching Lixit | Touching Lixit | Not Touching Lixit
Body | 3.73 | 4.66 | 1.00 | 1.00
Head | 5.64 | 6.98 | 1.51 | 1.50
Mouth | 4.55 | 3.96 | 1.22 | 0.85

SAR = specific absorption rate.

The uncertainty associated with the exposure field for the short-term exposures used in this assessment (Table A-25) was higher than that used within other assessments as there was not an integral number of stirrer rotations; the stirrer modulation aspect was increased from 0.22 dB to 0.33 dB to reflect the increased uncertainty. The highest uncertainty came from the homogeneity within the chamber as the animal phantom was moved from one location to another, as may be observed in the variation in absolute SAR in the same region within the animal. This effect will also be reflected in the relative SAR values. None of the measurements were outside these variation limits.

Table A-25 Uncertainties for the Water System Dosimetry

Equipment/Factor | Uncertainty Distribution | Divisor × | Coverage | Standard Uncertainty
Absolute Accuracy of the E- and H-field Probe | ±0.26 dB | Normal | 1 | ±0.26 dB
Frequency Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Dynamic Range Linearity | ±0.2 dB | Rectangular | √3 | ±0.12 dB
Isotropy | ±0.4 dB | Rectangular | √3 | ±0.12 dB
Temperature Probe Accuracy | ±0.05°C | Normal | 1 | ±0.02 dB
Homogeneity | ±0.65 dB | Normal | 1 | ±0.65 dB
Field Control | ±0.2 dB | Normal | 1 | ±0.20 dB
Stirrer Modulation | ±0.33 dB | Normal | 1 | ±0.33 dB
Combined Standard Uncertainty | | | | ±0.85 dB

### A.11.6 Implantable Temperature Sensors

Implantable temperature sensors (Star-Oddi, Gardebaer, Iceland) were needed to monitor body temperature during both exposure and nonexposure periods. Two features, safety and compatibility, were considered important. From a safety perspective, the presence of the implant should not lead to an increase in the SAR and hence heating. From a compatibility perspective, the implanted sensor should report the correct temperature without interference from electromagnetic fields. Any sensor that failed to meet one of these criteria would be deemed incompatible and/or not fit for purpose. To help elucidate safety and compatibility issues, dummy sensors with no internal electronics (i.e., with a shell filled only with epoxy) were used for comparison to the actual temperature sensors. The method involved placing a fiber temperature sensor close to the part of the implant considered to have the highest field enhancement; for micro-T and nano-T sensors, this position is close to the end of the visible internal metal parts. For the micro-HRT sensor, a position close to one of the electrodes was chosen.

#### A.11.6.1 Rat Implantable Sensors

##### A.11.6.1.1 Micro-T Sensor

For the micro-T implantable sensors, a dummy sensor was supplied. Figure A-66 shows the dummy sensor (with no visible internal metal parts) compared to the real sensor, which contained several metal parts (i.e., a battery, temperature sensor, and electronics) to log the readings to be read out at a later time. To allow the real micro-T sensor to be compared to the dummy sensor, both were placed in the same rat phantom symmetrically about the center, with the fiber temperature sensors close to the end of the visible internal metal parts (Figure A-67).

Figure A-66

Micro-T Sensor and the Dummy Sensor with Fiber Temperature Sensors

Figure shows the dummy sensor (white object, on the left, with no visible internal metal parts) compared to the real micro-T sensor (white object, on the right). For this comparison, the fiber temperature sensors (black fiber objects) are each positioned close to the end of the micro-T and dummy sensors.

Figure A-67

Placement of the Implantable Micro-T Sensor within the Rat Phantom

Figure shows placement of the fiber temperature sensor near the end of the implantable micro-T sensor within a rat phantom. On the opposite side of the same rat phantom, a dummy sensor was placed within the phantom (not shown).

The rate of temperature increase (SAR) was determined in two experiments; the averaged results are presented in Table A-26. The implantable micro-T temperature sensor recorded an increase in the SAR by 50% over that of the dummy sensor, indicating a potential for detrimental effects. The increased SAR exhibited by the real sensor is due to the metal conductors within the sensor. The metal conductors can short out the electric field, which leads to a field enhancement outside the implantable sensor. This can occur alongside field enhancements associated with the shape of the metallic parts, particularly any sharp edges or pointed structures. Any field enhancement will lead to increases in SAR and the potential for higher-than-expected temperature rises.

Table A-26 Comparison of Micro-T and Dummy Temperature Sensors in the Rat

| ΔT (mK/s) | Ratio (dB)
Micro-T | 1.44 | 1.48
Dummy | 0.97 | 1.7

##### A.11.6.1.2 Micro-HRT Sensor

For the micro-HRT, an implantable temperature and heart rate sensor and a dummy sensor with no internal electronics were supplied. To allow the real micro-HRT sensor to be compared to the dummy sensor, both the micro-HRT and dummy sensors were placed in the same rat phantom symmetrical about the center, with the fiber temperature sensors close to one of the surface electrodes (Figure A-68).

Figure A-68

Placement of the Implantable Micro-HRT Sensor within the Rat Phantom

Figure shows placement of the fiber temperature sensor near the electrodes on the implantable micro-HRT sensor within a rat phantom. A dummy sensor was also placed into the same rat phantom in a similar placement (not shown).

Table A-27 shows the results for the rate of temperature increase (SAR) close to the end of the micro-HRT implant. The area around the electrodes also showed increased SAR; while not as high as the value at the end of the implant, the SAR was still notably higher (36%). The SAR at the end of the micro-HRT implant increased by approximately 50%, similar to that observed with the micro-T implant presented in Table A-26.

Table A-27 Comparison of Micro-HRT and Dummy Heart Rate Sensors in the Rat

| ΔT (mK/s) | Ratio (dB)
Micro-HRT | 1.6305 | 1.36
Dummy | 1.2005 | 1.3

#### A.11.6.2 Mouse Implantable Sensors

In the case of the nano-T sensor, which can be implanted in either rats or mice, no dummy sensor was supplied. Thus, the nano-T sensor was compared to the background SAR at the same location in a second phantom. Two measurements were made with the relative positions of the phantoms reversed to account for chamber homogeneity. The measurement setup is shown in Figure A-69.

Figure A-69

Measurement Setup with Nano-T Sensor in Mouse Phantom

Table A-28 details the SAR results. There is little difference between the SAR with and without the implant, showing that the nano-T sensor was safe to implant within the rodents (i.e., that the temperature was not higher due to the presence of the sensor).

Table A-28 Temperature Increase Measured with Nano-T Sensor

| ΔT (mK/s) | Ratio (dB)
Nano-T | 7.53 | 1.03
No sensor | 7.33 | 0.12

#### A.11.6.3 Electromagnetic Compatibility of the Temperature Sensing

The ability of the implantable temperature sensors to report the temperature in the presence of the high-field strengths expected within the highest SAR chambers is of high importance for the temperature sensor to be fit for this purpose. To assess the potential for malfunction, the sensor was placed in a rat phantom for the exposures at 900 MHz and in a mouse phantom for the exposures at 1,900 MHz. The operation during GSM (pulsed) exposure and CW exposure was investigated, as these exposure conditions were the two extremes. The micro-size sensors (i.e., micro-T and micro-HRT) showed significant susceptibility to electromagnetic interference, particularly under GSM-pulsed exposure (Figure A-70 and Figure A-71, for micro-T and micro-HRT, respectively). With CW, the temperature level spiked only at the onset of exposure; however, this meant that the micro-size sensors were not considered appropriate for use in these experiments. The nano-T sensor also showed a small amount of interference with GSM signals, but the increase in temperature was reported with reasonable fidelity (Figure A-72). Based on these results, the nano-T sensors were considered appropriate for use in the planned experiments.

Figure A-70

Micro-T Sensor Logged Temperature Values and the Applied Field Strength

Figure shows the temperature values (orange) and the applied field strength (blue) for GSM and CW signals. GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation; CW = continuous wave.

Figure A-71

Micro-HRT Sensor Logged Temperature Values and the Applied Field Strength

Figure shows the temperature values (orange) and the applied field strength (blue) for GSM and CW signals. GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation; CW = continuous wave.

Figure A-72

Nano-T Sensor Logged Temperature Values and the Applied Field Strength

Figure shows the temperature values (orange) and the applied field strength (blue) for GSM and CW signals. GSM = Global System for Mobile Communications-modulated cell phone radiofrequency radiation; CW = continuous wave.

## A.12 Infrared Cameras

The infrared (IR) camera chosen was the Transcend DrivePro Body 1080p camera (Figure A-73). The cameras were placed within Faraday boxes to provide shielding for error and artifact-free operation in the high-field environment of the reverberation chamber. Furthermore, because of the all-metal construction, there was no absorption of energy, and the incident field was scattered. As the reverberation chamber environment was designed to give maximum scattering of the fields, the camera had no impact on the exposures provided. The cameras were placed more than half a wavelength from the nearest cage, and because the cameras were mounted on the metallic door, their presence had no impact on the RF field.

Figure A-73

The Transcend DrivePro Body 1080p Camera