# Peer Review

The draft NTP Technical Report on the Toxicity Studies of a Gum Guggul Extract Formulation Administered by Gavage to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of this NTP study were appropriate and ensured that this Toxicity Study Report presents the experimental results and conclusions fully and clearly.

- Bob Benson, Ph.D.
  Drinking Water Toxicologist
  United States Environmental Protection Agency, Region 8
  Denver, Colorado, USA
- John Pierce Wise, Sr., Ph.D.
  Professor, Pharmacology and Toxicology
  Department of Pharmacology and Toxicology, School of Medicine
  University of Louisville
  Louisville, Kentucky, USA