# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  T.D. Hubbard, Ph.D., Study Scientist
  S.A. Elmore, D.V.M., Study Pathologist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  R.P. Frawley, M.S.
  D.R. Germolec, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  G.K. Roberts, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
  M.E. Wyde, Ph.D.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Battelle, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M. Hejtmancik, Ph.D., Principal Investigator
  D.A. Contos, M.S.
  D.K. Gerken, Ph.D.
  K.A.B. Knostman, D.V.M., Ph.D.
  M.J. Ryan, D.V.M., Ph.D.
  A.J. Skowronek, D.V.M., Ph.D.
- Conducted prestart chemistry activities and dose formulations
  S.W. Graves, B.S., Principal Investigator
  B. Burback, Ph.D.
  K.A. Carrico, B.A.
  D.A. Contos, M.S.
- MRIGlobal, Kansas City, Missouri, USA
  Conducted preliminary chemistry activities and contaminant analysis
  J.W. Algaier, Ph.D., Principal Investigator
  D. Messer, Ph.D.
  L. Siemann, B.S.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology quality assessment review
  C.C. Shackelford, D.V.M., Ph.D.
- Pathology Associates, A Division of Charles River Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted NTP Pathology Peer Review (3-month studies)
  L. Kooistra, D.V.M., Ph.D.
- RTI International, Research Triangle Park, North Carolina, USA
  Conducted human in vitro activity assays
  J.M. Matthews, Ph.D., Principal Investigator
  S. Black, B.S.
- Provided sperm count and vaginal cytology evaluation (SCVCE) analysis
  R.W. Tyl, Ph.D., Principal Investigator
  K. Basham, B.S.
  M. Marr, B.A.