# References

1 Shah R Gulati V Palombo EA Pharmacological properties of guggulsterones, the major active components of gum guggul. Phytother Res. 2012;26(11):1594–1605. 10.1002/ptr.4647 22388973
2 Atal CK Gupta OP Afaq SH Commiphora mukul: source of guggal in Indian systems of medicine. Econ Bot. 1975;29(3):209–218.10.1007/BF02873167
3 Dastur JF Medicinal plants of India and Pakistan. Bombay, India: Taraporevala and Sons; 1977.
4 Indian Council of Medical Research Medicinal plants of India. New Delhi, India; 1987.
5 Sarup P Bala S Kamboj S Pharmacology and phytochemistry of oleo-gum resin of Commiphora wightii (guggulu). Scientifica (Cairo). 2015;2015:1–14. 10.1155/2015/138039 26587309
6 Deng R Therapeutic effects of guggul and its constituent guggulsterone: cardiovascular benefits. Cardiovasc Drug Rev. 2007;25(4):375–390. 10.1111/j.1527-3466.2007.00023.x 18078436
7 Bajaj AG Dev S Chemistry of ayurvedic crude drugs—V: Guggulu (resin from commiphora mukul)—5 some new steroidal components and, stereochemistry of guggulsterol-I at C-20 and C-22. Tetrahedron. 1982;38(19):2949–2954.10.1016/0040-4020(82)85024-2
8 Mesrob B Nesbitt C Misra R Pandey RC High-performance liquid chromatographic method for fingerprinting and quantitative determination of E- and Z-guggulsterones in Commiphora mukul resin and its products. J Chromatogr B Biomed Appl. 1998;720(1-2):189–196. 10.1016/S0378-4347(98)00433-2 9892081
9 Chander R, Khanna AK, Kapoor NK. Lipid lowering activity of guggulsterone from Commiphora mukul in hyperlipaemic rats. Phytother Res. 1996; 10(6):508-511. 10.1002/(SICI)1099-1573(199609)10:6<508:AID-PTR895>3.0.CO;2-P
10 Cheon JH Kim JS Kim JM Kim N Jung HC Song IS Plant sterol guggulsterone inhibits nuclear factor-kappaB signaling in intestinal epithelial cells by blocking IkappaB kinase and ameliorates acute murine colitis. Inflamm Bowel Dis. 2006;12(12):1152–1161. 10.1097/01.mib.0000235830.94057.c6 17119390
11 Meselhy MR Inhibition of LPS-induced NO production by the oleogum resin of Commiphora wightii and its constituents. Phytochemistry. 2003;62(2):213–218. 10.1016/S0031-9422(02)00388-6 12482459
12 Singh RB Niaz MA Ghosh S Hypolipidemic and antioxidant effects of Commiphora mukul as an adjunct to dietary therapy in patients with hypercholesterolemia. Cardiovasc Drugs Ther. 1994;8(4):659–664. 10.1007/BF00877420 7848901
13 Urizar NL Liverman AB Dodds DNT Silva FV Ordentlich P Yan Y Gonzalez FJ Heyman RA Mangelsdorf DJ Moore DD A natural product that lowers cholesterol as an antagonist ligand for FXR. Science. 2002;296(5573):1703–1706. 10.1126/science.1072891 11988537
14 Cui J Huang L Zhao A Lew JL Yu J Sahoo S Meinke PT Royo I Peláez F Wright SD Guggulsterone is a farnesoid X receptor antagonist in coactivator association assays but acts to enhance transcription of bile salt export pump. J Biol Chem. 2003;278(12):10214–10220. 10.1074/jbc.M209323200 12525500
15 Deng R Yang D Radke A Yang J Yan B The hypolipidemic agent guggulsterone regulates the expression of human bile salt export pump: dominance of transactivation over farsenoid X receptor-mediated antagonism. J Pharmacol Exp Ther. 2007;320(3):1153–1162. 10.1124/jpet.106.113837 17135343
16 Brobst DE Ding X Creech KL Goodwin B Kelley B Staudinger JL Guggulsterone activates multiple nuclear receptors and induces CYP3A gene expression through the pregnane X receptor. J Pharmacol Exp Ther. 2004;310(2):528–535. 10.1124/jpet.103.064329 15075359
17 Kulhari A Sheorayan A Chaudhury A Sarkar S Kalia RK Quantitative determination of guggulsterone in existing natural populations of Commiphora wightii (Arn.) Bhandari for identification of germplasm having higher guggulsterone content. Physiol Mol Biol Plants. 2014;21(1):71–81. 10.1007/s12298-014-0271-1 25648764
18 Bhatt JR Nair MNB Ram HYM Enhancement of oleo-gum resin production in Commiphora wightii by improved tapping technique. Curr Sci. 1989;58(7):349–357.
19 Samanta JN Mandal K Maiti S A novel pathovar of Xanthomonas axonopodis causes gumming of Guggal (Commiphora wightii). Eur J Plant Pathol. 2013;135(1):115–125.10.1007/s10658-012-0070-x
20 Ved D, Saha D, Ravikumar K, Haridasan K. Commiphora wightii. The IUCN Red List of Threatened Species; 2015. https://www.iucnredlist.org/species/31231/50131117
21 Saini LS Rajput SK Rathore TR Tomar UK Non-destructive harvesting of oleo-gum resin in Commiphora wightii (Arnott) Bhandari—A critically endangered plant. Ind Crops Prod. 2018;113:259–265.10.1016/j.indcrop.2018.01.057
22 Dixit AM Subba Rao SV Observation on distribution and habitat characteristics of Gugal (Commiphora wightii) in the arid region of Kachchh, Gujarat (India). Trop Ecol. 2000;41(1):81–88.
23 United States Pharmacoepia (USP). Dietary supplements compendium: Guggul. 2015. p. 117-119.
24 Clarke TC Black LI Stussman BJ Barnes PM Nahin RL Trends in the use of complementary health approaches among adults: United States, 2002–2012. Natl Health Stat Rep. 2015;(79):1. 25671660
25 Shipkowski KA Betz JM Birnbaum LS Bucher JR Coates PM Hopp DC MacKay D Oketch-Rabah H Walker NJ Welch C Naturally complex: Perspectives and challenges associated with Botanical Dietary Supplement Safety assessment. Food Chem Toxicol. 2018;118:963–991. 10.1016/j.fct.2018.04.007 29626579
26 Ulbricht C Basch E Szapary P Hammerness P Axentsev S Boon H Kroll D Garraway L Vora M Woods J Guggul for hyperlipidemia: A review by the Natural Standard Research Collaboration. Complement Ther Med. 2005;13(4):279–290. 10.1016/j.ctim.2005.08.003 16338199
27 World Health Organization (WHO). Gummi gugguli. In: WHO Monographs on Selected Medicinal Plants Vol 3. 2007. p. 169-181.
28 Indian Ministry of Health and Family Welfare. Indian pharmacopoeia. Vol 2. New Delhi, India: Delhi: Controller of Publications; 1996. p. 357-358.
29 Badmaev V Majeed M The 99% guggulsterones tragedy. Nutraceuticals; 2004. p. 11–12.
30 Agarwal RC Singh SP Saran RK Das SK Sinha N Asthana OP Gupta PP Nityanand S Dhawan BN Agarwal SS Clinical trial of gugulipid—a new hypolipidemic agent of plant origin in primary hyperlipidemia. Indian J Med Res. 1986;84:626–634. 3552974
31 Gopal K Saran RK Nityanand S Gupta PP Hasan M Das SK Sinha N Agarwal SS Clinical trial of ethyl acetate extract of gum gugulu (gugulipid) in primary hyperlipidemia. J Assoc Physicians India. 1986;34(4):249–251. 3531151
32 Kuppurajan K Rajagopalan SS Rao TK Sitaraman R Effect of guggulu (Commiphora mukul—Engl.) on serum lipids in obese, hypercholesterolemic and hyperlipemic cases. J Assoc Physicians India. 1978;26(5):367–373. 730716
33 Malhotra SC Ahuja MM Sundaram KR Long term clinical studies on the hypolipidaemic effect of Commiphora mukul (Guggulu) and clofibrate. Indian J Med Res. 1977;65(3):390–395. 924552
34 Nityanand S Srivastava JS Asthana OP Clinical trials with gugulipid. A new hypolipidaemic agent. J Assoc Physicians India. 1989;37(5):323–328. 2693440
35 Verma SK Bordia A Effect of Commiphora mukul (gum guggulu) in patients of hyperlipidemia with special reference to HDL-cholesterol. Indian J Med Res. 1988;87:356–360. 3169888
36 Szapary PO Wolfe ML Bloedon LT Cucchiara AJ DerMarderosian AH Cirigliano MD Rader DJ Guggulipid for the treatment of hypercholesterolemia: A randomized controlled trial. JAMA. 2003;290(6):765–772. 10.1001/jama.290.6.765 12915429
37 Tripathi YB Malhotra OP Tripathi SN Thyroid stimulating action of Z-guggulsterone obtained from Commiphora mukul. Planta Med. 1984;50(1):78–80.10.1055/s-2007-969626
38 Abdel-Rahman A Anyangwe N Carlacci L Casper S Danam RP Enongene E Erives G Fabricant D Gudi R Hilmas CJ The safety and regulation of natural products used as foods and food ingredients. Toxicol Sci. 2011;123(2):333–348. 10.1093/toxsci/kfr198 21821733
39 Verma N Singh SK Gupta RC Pharmacokinetics of guggulsterone after intravenous and oral administration in rats. Pharm Pharmacol Commun. 1999;5(5):349–354. 10.1211/146080899128734956
40 Chhonker YS Chandasana H Mukkavilli R Prasad YD Laxman TS Vangala S Bhatta RS Assessment of in vitro metabolic stability, plasma protein binding, and pharmacokinetics of E- and Z-guggulsterone in rat. Drug Test Anal. 2016;8(9):966–975. 10.1002/dta.1885 26608935
41 Bhatta RS Kumar D Chhonker YS Jain GK Simultaneous estimation of E- and Z- isomers of guggulsterone in rabbit plasma using liquid chromatography tandem mass spectrometry and its application to pharmacokinetic study. Biomed Chromatogr. 2011;25(9):1054–1060. 10.1002/bmc.1574 21268049
42 Yang D Yang J Shi D Xiao D Chen Y-T Black C Deng R Yan B Hypolipidemic agent Z-guggulsterone: metabolism interplays with induction of carboxylesterase and bile salt export pump. J Lipid Res. 2012;53(3):529–539. 10.1194/jlr.M014688 22246918
43 Dalvi SS Nayak VK Pohujani SM Desai NK Kshirsagar NA Gupta KC Effect of gugulipid on bioavailability of diltiazem and propranolol. J Assoc Physicians India. 1994;42(6):454–455. 7852226
44 Badmaev V Majeed M Pachetti B Prakash L Standardization of Commiphora mukul in dislipidemia and cardiovascular disease. Nutrafoods. 2003;2(2):45–51.
45 Bagi MK Kakrani HK Kalyani GA Satyanarayana D Manvi FV Preliminary pharmacological studies of essential oil from Commiphora mukul. Fitoterapia. 1985:56.
46 Panda S Kar A Gugulu (Commiphora mukul) induces triiodothyronine production: possible involvement of lipid peroxidation. Life Sci. 1999;65(12):137–141. 10.1016/S0024-3205(99)00369-0 10503949
47 Bordia A Chuttani SK Effect of gum guggulu on fibrinolysis and platelet adhesiveness in coronary heart disease. Indian J Med Res. 1979;70:992–996. 396237
48 Gaur SPS Garg RK Kar AM Purohit YK Gupta A Gugulipid, a new hypolipidaemic agent, in patients of acute ischaemic stroke: effect on clinical outcome, platelet function and serum lipids. Asia Pacific J Pharmacol. 1997;12(3-4):65–69.
49 Sahni S Hepfinger CA Sauer KA Guggulipid use in hyperlipidemia: case report and review of the literature. Am J Health Syst Pharm. 2005;62(16):1690–1692. 10.2146/ajhp040580 16085931
50 Grieco A Miele L Pompili M Biolato M Vecchio FM Grattagliano I Gasbarrini G Acute hepatitis caused by a natural lipid-lowering product: When “alternative” medicine is no “alternative” at all. J Hepatol. 2009;50(6):1273–1277. 10.1016/j.jhep.2009.02.021 19398239
51 Food and Drug Administration (FDA). MedWatch: The FDA safety information and adverse event reporting program (online). Silver Spring, MD; 2014. https://www.fda.gov/safety/medwatch/default.htm [Accessed: November 12, 2018]
52 Amma MK Malhotra N Suri RK Arya OP Dani HM Sareen K Effect of oleoresin of gum guggul (Commiphora mukul) on the reproductive organs of female rat. Indian J Exp Biol. 1978;16(9):1021–1023. 721150
53 Indian Ministry of Health and Family Welfare Studies on gugglu. New Delhi, India: Central Council for Research in Ayurveda and Siddha; 1989.
54 Yamada T Sugimoto K Drug Discovery from Mother Nature. Springer; 2016. Guggulsterone and its role in chronic diseases; p. 329–361. 10.1007/978-3-319-41342-6_15
55 Frawley RP Smith M Cesta MF Hayes-Bouknight S Blystone C Kissling GE Harris S Germolec D Immunotoxic and hepatotoxic effects of perfluoro-n-decanoic acid (PFDA) on female Harlan Sprague–Dawley rats and B6C3F1/N mice when administered by oral gavage for 28 days. J Immunotoxicol. 2018;15(1):41–52. 10.1080/1547691X.2018.1445145 29514525
56 Xue-jun Y De-xiang L Hechuan W Yu Z A study on the mutagenicity of 102 raw pharmaceuticals used in Chinese traditional medicine. Mutat Res. 1991;260(1):73–82. 10.1016/0165-1218(91)90082-W 2027343
57 Macha MA Matta A Chauhan SS Siu KWM Ralhan R Guggulsterone targets smokeless tobacco induced PI3K/Akt pathway in head and neck cancer cells. PLoS One. 2011;6(2). 10.1371/journal.pone.0014728 21383988
58 Yamada T Osawa S Ikuma M Kajimura M Sugimoto M Furuta T Iwaizumi M Sugimoto K Guggulsterone, a plant-derived inhibitor of NF-TB, suppresses CDX2 and COX-2 expression and reduces the viability of esophageal adenocarcinoma cells. Digestion. 2014;90(3):208–217. 10.1159/000365750 25427631
59 American Herbal Productions Association (AHPA). Heavy metals: Analysis and limits in herbal dietary supplements. Silver Spring, MD: AHPA; 2009. http://www.naturalhealthresearch.org/wp-content/uploads/2013/02/09_1214_AHPA_Heavy-Metals-White-Paper-Revised.pdf
60 International Council for Harmonisation of Technical Requirements for Pharmaceuticals for Human Use (ICH) Guideline for elemental impurities Q3D(R1). Amsterdam, The Netherlands: European Medicines Agency, Committee for Human Medicinal Products; 2019.
61 Maronpot R Boorman G Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. 10.1177/019262338201000210 28094716
62 Boorman G Montgomery C Eustis S Wolfe M McConnell E Hardisty J Quality assurance in pathology for rodent carcinogenicity studies. In: Milman H Weisburger Eeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
63 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
64 Armitage P Statistical methods in medical research. New York (NY): John Wiley and Sons; 1971. p. 362–365.
65 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. 10.1080/01621459.1955.10501294
66 Williams D A test for differences between treatment means when several dose levels are compared with a zero-dose control. Biometrics. 1971;27:103–117. 10.2307/2528930 5547548
67 Williams D The comparison of several dose levels with a zero dose control. Biometrics. 1972:519–531. 10.2307/2556164 5037867
68 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977:386–389. 10.2307/2529789 884197
69 Williams D A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986:183–186. 10.2307/2531254 3719054
70 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252. 10.1080/00401706.1964.10490181
71 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1/2):133–145. 10.2307/2333011
72 Dixon W Massey F Introduction to statistical analysis. 2nd ed. New York (NY): McGraw Hill; 1957. p. 145–147, 276–278, 412.
73 Wilcoxon F Individual comparisons by ranking methods. Biometrics. 1945;1:80–83. 10.2307/3001968
74 Code of Federal Regulations (CFR). 21:Part 58.
75 Witt KL Livanos E Kissling GE Torous DK Caspary W Tice RR Recio L Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008;649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
76 Kissling GE Dertinger SD Hayashi M MacGregor JT Sensitivity of the erythrocyte micronucleus assay: dependence on number of cells scored and inter-animal variability. Mutat Res. 2007;634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
77 Igl B-W Bitsch A Bringezu F Chang S Dammann M Frötschl R Harm V Kellner R Krzykalla V Lott J The rat bone marrow micronucleus test: statistical considerations on historical negative control data. Regul Toxicol Pharmacol. 2019;102:13–22. 10.1016/j.yrtph.2018.12.009 30572081
78 Hickman D Wang J-P Wang Y Unadkat JD Evaluation of the selectivity of in vitro probes and suitability of organic solvents for the measurement of human cytochrome P450 monooxygenase activities. Drug Metab Dispos. 1998;26(3):207–215. 9492382
79 Harris JW Rahman A Kim B-R Guengerich FP Collins JM Metabolism of taxol by human hepatic microsomes and liver slices: participation of cytochrome P450 3A4 and an unknown P450 enzyme. Cancer Res. 1994;54(15):4026–4035. 7913410
80 Miners JO Smith KJ Robson RA McManus ME Veronese ME Birkett DJ Tolbutamide hydroxylation by human liver microsomes: kinetic characterisation and relationship to other cytochrome P-450 dependent xenobiotic oxidations. Biochem Pharmacol. 1988;37(6):1137–1144. 10.1016/0006-2952(88)90522-9 3355588
81 Koop DR Hydroxylation of p-nitrophenol by rabbit ethanol-inducible cytochrome P-450 isozyme 3a. Mol Pharmacol. 1986;29(4):399–404. 3702859
82 Laurenzana EM Sorrels SL Owens SM Antipeptide antibodies targeted against specific regions of rat CYP2D1 and human CYP2D6. Drug Metab Dispos. 1995;23(2):271–278. 7736924
83 Clarke SE Baldwin SJ Bloomer JC Ayrton AD Sozio RS Chenery RJ Lauric acid as a model substrate for the simultaneous determination of cytochrome P450 2E1 and 4A in hepatic microsomes. Chem Res Toxicol. 1994;7(6):836–842. 10.1021/tx00042a018 7696540
84 Patki KC von Moltke LL Greenblatt DJ In vitro metabolism of midazolam, triazolam, nifedipine, and testosterone by human liver microsomes and recombinant cytochromes p450: role of cyp3a4 and cyp3a5. Drug Metab Dispos. 2003;31(7):938–944. 10.1124/dmd.31.7.938 12814972
85 Wood AW Ryan D Thomas P Levin W Regio-and stereoselective metabolism of two C19 steroids by five highly purified and reconstituted rat hepatic cytochrome P-450 isozymes. J Biol Chem. 1983;258(14):8839–8847. 6863312
86 National Toxicology Program (NTP). TOX-99: Pathology tables, survival and growth curves from NTP short-term, immunotoxicology, in vitro activity (human), and micronucleus studies. Research Triangle Park, NC; 2020. 10.22427/NTP-DATA-TOX-99
87 Sharma B Salunke R Srivastava S Majumder C Roy P Effects of guggulsterone isolated from Commiphora mukul in high fat diet induced diabetic rats. Food Chem Toxicol. 2009;47(10):2631–2639. 10.1016/j.fct.2009.07.021 19635521
88 Sharma JN Sharma JN Comparison of the anti-inflammatory activity of Commiphora mukul (an indigenous drug) with those of phenylbutazone and ibuprofen in experimental arthritis induced by mycobacterial adjuvant. Arzneimittelforschung. 1977;27(7):1455–1457. 578471
89 Shishodia S Harikumar KB Dass S Ramawat KG Aggarwal BB The guggul for chronic diseases: ancient medicine, modern targets. Anticancer Res. 2008;28 6A:3647–3664. 19189646
90 Yang JY Della-Fera MA Baile CA Guggulsterone inhibits adipocyte differentiation and induces apoptosis in 3T3-L1 cells. Obesity (Silver Spring). 2008;16(1):16–22. 10.1038/oby.2007.24 18223606
91 Leiva A Contreras-Duarte S Amigo L Sepulveda E Boric M Quinones V Busso D Rigotti A Gugulipid causes hypercholesterolemia leading to endothelial dysfunction, increased atherosclerosis, and premature death by ischemic heart disease in male mice. PLoS One. 2017;12(9):e0184280. 10.1371/journal.pone.0184280 28910310
92 Deng R Yang D Yang J Yan B Oxysterol 22(R)-hydroxycholesterol induces the expression of the bile salt export pump through nuclear receptor farsenoid X receptor but not liver X receptor. J Pharmacol Exp Ther. 2006;317(1):317–325. 10.1124/jpet.105.097758 16371446
93 Bovee TFH Schoonen WGEJ Hamers ARM Bento MJ Peijnenburg AACM Screening of synthetic and plant-derived compounds for (anti)estrogenic and (anti)androgenic activities. Anal Bioanal Chem. 2008;390(4):1111–1119. 10.1007/s00216-007-1772-3 18188547
94 Burris TP Montrose C Houck KA Osborne HE Bocchinfuso WP Yaden BC Cheng CC Zink RW Barr RJ Hepler CD The hypolipidemic natural product guggulsterone is a promiscuous steroid receptor ligand. Mol Pharmacol. 2005;67(3):948–954. 10.1124/mol.104.007054 15602004
95 Ho RH Tirona RG Leake BF Glaeser H Lee W Lemke CJ Wang Y Kim RB Drug and bile acid transporters in Rosuvastatin hepatic uptake: Function, expression, and pharmacogenetics. Gastroenterology. 2006;130(6):1793–1806. 10.1053/j.gastro.2006.02.034 16697742
96 Memorial Sloan-Kettering Cancer Center. Guggul (Commiphora mukul). 2012. https://www.mskcc.org/cancer-care/integrative-medicine/herbs/guggul
97 Qato DM Alexander GC Conti RM Johnson M Schumm P Lindau ST Use of prescription and over-the-counter medications and dietary supplements among older adults in the United States. JAMA. 2008;300(24):2867–2878. 10.1001/jama.2008.892 19109115
98 Guengerich FP Cytochrome P450s and other enzymes in drug metabolism and toxicity. AAPS J. 2006;8(1):E101–E111. 10.1208/aapsj080112 16584116
99 Dertinger SD Camphausen K MacGregor JT Bishop ME Torous DK Avlasevich S Cairns S Tometsko CR Menard C Muanza T Three‐color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004;44(5):427–435. 10.1002/em.20075 15517570