# Conclusions

Under the conditions of the 3-month gavage studies, administration of the selected GGE formulation resulted in increased globulin concentrations and decreased bile acid, cholesterol, and phospholipid concentrations in rats, whereas increases in cholesterol and phospholipid concentrations were observed in mice. Decreased mean number of homogenization-resistant spermatids was evident in mice administered the GGE formulation, suggesting the testes might be a target organ of GGE toxicity (lowest-observed-effect level = 62.5 mg/kg/day). Male and female rats displayed significantly increased absolute and relative liver weights that were related to the GGE formulation dose administered. Additionally, increased hepatic CYP3A and CYP2B activity was observed in both test species, and metabolic potential was altered in human in vitro assays, suggesting an increased potential for dietary supplement-drug pharmacokinetic interactions.